# Results

## Three-month Study in Rats

All core study male rats survived to the end of the study (Table 2). Three 600 mg/kg core study females died within 4 days of the start of the study; two of the females were found dead with no specific cause identified, and one female was euthanized due to its moribund condition, which included ataxia, abnormal breathing, and nasal/eye discharge. The final mean body weight and mean body weight gain of 600 mg/kg males were significantly less (20% and 30% less, respectively) than those of the vehicle controls (Table 2 and Figure 3). The final mean body weights and mean body weight gains of the remaining dosed groups of males and all dosed groups of females were similar (within 4%) to those of the vehicle control groups. Clinical findings included nasal and eye discharge observed in one 30 mg/kg male, one 300 mg/kg male, and three 600 mg/kg males on days 36, 22, and 15, respectively, and in one 10 mg/kg female on day 29. The livers of all 300 and 600 mg/kg rats surviving to the end of the study were enlarged at necropsy.

Table 2 Survival and Body Weights of Rats in the Three-month Gavage Study of Myristicin^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 110 ± 5 | 331 ± 6 | 222 ± 3
10 | 10/10 | 110 ± 5 | 327 ± 5 | 217 ± 4 | 99
30 | 10/10 | 106 ± 5 | 334 ± 7 | 228 ± 4 | 101
100 | 10/10 | 107 ± 4 | 335 ± 7 | 227 ± 7 | 101
300 | 10/10 | 106 ± 5 | 317 ± 9 | 211 ± 6 | 96
600 | 10/10 | 109 ± 5 | 264 ± 6** | 154 ± 4** | 80
Female
0 | 10/10 | 99 ± 3 | 179 ± 4 | 81 ± 3
10 | 10/10 | 98 ± 2 | 182 ± 3 | 84 ± 3 | 102
30 | 10/10 | 95 ± 3 | 178 ± 4 | 83 ± 4 | 100
100 | 10/10 | 96 ± 2 | 179 ± 2 | 83 ± 2 | 100
300 | 10/10 | 95 ± 3 | 172 ± 2 | 77 ± 3 | 96
600 | 7/10^c^ | 96 ± 3 | 172 ± 7 | 72 ± 5 | 96

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of deaths: 1.

Figure 3

Growth Curves for Rats Administered Myristicin by Gavage for Three Months

On day 3, significant increases in the male rat erythron were observed, most consistently in the 600 mg/kg group; this was characterized by significantly increased erythrocyte count, hemoglobin concentration, and hematocrit values (Table 3 and Table B-1). These increases were consistent with hemoconcentration (i.e., dehydration) and supported by significantly increased blood urea nitrogen (BUN) concentration in 600 mg/kg males on day 3. These male erythron changes resolved by week 14. On day 22, the erythrocyte count, hemoglobin concentration, and hematocrit values were significantly decreased in female rats, generally in the 300 and 600 mg/kg groups. At week 14, similar significantly decreased incidences were observed in 300 and 600 mg/kg females, but the effect was minimal in comparison. The reason for the mild decrease in the erythron in females is uncertain.

Table 3 Selected Clinical Pathology Data for Rats in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Male
Hematology
n
Day 3 | 9 | 9 | 10 | 10 | 10 | 10
Day 22 | 10 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (auto) (%)
Day 3 | 43.0 ± 0.6 | 43.9 ± 0.6 | 43.3 ± 0.5 | 43.0 ± 0.5 | 44.3 ± 0.5 | 45.4 ± 0.6**
Day 22 | 45.1 ± 0.3 | 43.9 ± 0.2 | 45.6 ± 0.5 | 46.2 ± 0.4 | 44.2 ± 0.4 | 42.4 ± 0.9*
Week 14 | 47.3 ± 0.5 | 47.3 ± 0.3 | 46.5 ± 0.4 | 46.9 ± 0.4 | 46.3 ± 0.4 | 46.4 ± 0.3
Manual hematocrit (%)
Day 3 | 43.2 ± 0.4 | 44.6 ± 0.5 | 43.6 ± 0.4^b^ | 43.7 ± 0.4^b^ | 45.3 ± 0.4**^b^ | 46.3 ± 0.5**
Day 22 | 45.3 ± 0.5 | 45.1 ± 0.3 | 46.3 ± 0.4 | 46.4 ± 0.4 | 45.0 ± 0.5 | 43.3 ± 0.7
Week 14 | 47.6 ± 0.5 | 46.7 ± 0.4 | 46.8 ± 0.4 | 47.0 ± 0.4 | 46.3 ± 0.4 | 46.1 ± 0.3
Hemoglobin (g/dL)
Day 3 | 13.5 ± 0.2 | 13.8 ± 0.1 | 13.6 ± 0.1 | 13.6 ± 0.2 | 14.1 ± 0.1** | 14.7 ± 0.1**
Day 22 | 14.1 ± 0.1 | 13.8 ± 0.1 | 14.2 ± 0.1 | 14.3 ± 0.1 | 14.0 ± 0.1 | 13.4 ± 0.3
Week 14 | 15.0 ± 0.1 | 14.8 ± 0.1 | 14.7 ± 0.2 | 14.8 ± 0.1 | 14.6 ± 0.1 | 14.5 ± 0.1**
Erythrocytes (10^6^/μL)
Day 3 | 7.41 ± 0.15 | 7.49 ± 0.09 | 7.43 ± 0.10 | 7.39 ± 0.12 | 7.60 ± 0.09 | 7.90 ± 0.10**
Day 22 | 7.99 ± 0.09 | 7.78 ± 0.04 | 8.05 ± 0.10 | 8.16 ± 0.07 | 7.81 ± 0.07 | 7.70 ± 0.16
Week 14 | 9.25 ± 0.11 | 9.19 ± 0.07 | 9.11 ± 0.09 | 9.07 ± 0.07 | 9.00 ± 0.07 | 9.13 ± 0.06
Segmented neutrophils (10^3^/μL)
Day 3 | 1.46 ± 0.08 | 1.48 ± 0.07 | 1.60 ± 0.10 | 1.51 ± 0.07 | 1.51 ± 0.11 | 1.36 ± 0.09
Day 22 | 1.54 ± 0.08 | 1.52 ± 0.11 | 1.64 ± 0.11 | 1.72 ± 0.09 | 1.77 ± 0.11 | 1.62 ± 0.09
Week 14 | 1.53 ± 0.06 | 1.98 ± 0.20 | 1.85 ± 0.10 | 1.53 ± 0.07 | 1.96 ± 0.10* | 1.90 ± 0.08*
Clinical Chemistry
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 22 | 10 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 12.9 ± 0.4^c^ | 13.5 ± 0.7 | 13.3 ± 0.3 | 13.8 ± 0.6^b^ | 14.2 ± 0.8 | 17.0 ± 0.8**^c^
Day 22 | 10.1 ± 0.4 | 10.1 ± 0.5 | 10.2 ± 0.5 | 13.1 ± 0.8* | 12.0 ± 0.4* | 12.3 ± 0.6*
Week 14 | 13.3 ± 0.6 | 13.1 ± 0.7 | 13.4 ± 0.4 | 14.1 ± 0.6 | 14.0 ± 0.4 | 15.8 ± 0.8*
Creatinine (mg/dL)
Day 3 | 0.61 ± 0.01^b^ | 0.61 ± 0.01 | 0.60 ± 0.00 | 0.60 ± 0.00^b^ | 0.61 ± 0.01 | 0.65 ± 0.03
Day 22 | 0.62 ± 0.01 | 0.60 ± 0.00 | 0.61 ± 0.01 | 0.61 ± 0.02 | 0.61 ± 0.01 | 0.62 ± 0.01
Week 14 | 0.70 ± 0.01 | 0.74 ± 0.04 | 0.71 ± 0.01 | 0.73 ± 0.02 | 0.75 ± 0.02* | 0.76 ± 0.02*
Total protein (g/dL)
Day 3 | 5.5 ± 0.1^c^ | 5.7 ± 0.1 | 5.5 ± 0.1 | 5.5 ± 0.1^b^ | 5.4 ± 0.1 | 5.4 ± 0.1^c^
Day 22 | 6.1 ± 0.1 | 5.8 ± 0.1* | 6.0 ± 0.1 | 6.0 ± 0.1 | 6.1 ± 0.1 | 6.4 ± 0.1
Week 14 | 7.2 ± 0.1 | 7.1 ± 0.1 | 7.2 ± 0.1 | 7.2 ± 0.1 | 7.7 ± 0.1** | 8.0 ± 0.1**
Albumin (g/dL)
Day 3 | 3.9 ± 0.1 | 4.0 ± 0.0 | 3.9 ± 0.0 | 3.9 ± 0.1 | 3.8 ± 0.1 | 3.9 ± 0.0
Day 22 | 4.3 ± 0.0 | 4.1 ± 0.0 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.1 ± 0.0 | 4.4 ± 0.1
Week 14 | 4.6 ± 0.0 | 4.5 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.8 ± 0.0* | 5.0 ± 0.0**
Cholesterol (mg/dL)
Day 3 | 88 ± 2 | 90 ± 2 | 92 ± 2 | 101 ± 3** | 108 ± 4** | 103 ± 3**^b^
Day 22 | 79 ± 1 | 73 ± 1 | 79 ± 1 | 81 ± 1 | 88 ± 2** | 122 ± 4**
Week 14 | 79 ± 1 | 77 ± 2 | 83 ± 2 | 85 ± 1* | 113 ± 2** | 149 ± 3**
Triglycerides (mg/dL)
Day 3 | 107 ± 8^b^ | 135 ± 28 | 110 ± 9 | 115 ± 4 | 127 ± 8 | 266 ± 34**^c^
Day 22 | 98 ± 8 | 101 ± 6 | 112 ± 8 | 80 ± 12 | 121 ± 10 | 179 ± 17**
Week 14 | 120 ± 9 | 113 ± 8 | 135 ± 10 | 128 ± 9 | 164 ± 9** | 192 ± 20**
Alanine aminotransferase (IU/L)
Day 3 | 64 ± 3 | 66 ± 4 | 64 ± 2 | 67 ± 2 | 72 ± 3* | 78 ± 5*
Day 22 | 49 ± 1 | 51 ± 2 | 51 ± 1 | 55 ± 2* | 56 ± 1** | 62 ± 2**
Week 14 | 64 ± 2 | 61 ± 3 | 60 ± 3 | 58 ± 2 | 60 ± 2 | 84 ± 3*
Alkaline phosphatase (IU/L)
Day 3 | 641 ± 29^d^ | 669 ± 24 | 623 ± 26^c^ | 616 ± 17^d^ | 661 ± 25^b^ | 537 ± 24^b^
Day 22 | 453 ± 10 | 435 ± 6 | 447 ± 12 | 399 ± 16* | 377 ± 7** | 330 ± 11**
Week 14 | 249 ± 9 | 265 ± 7 | 261 ± 5 | 249 ± 6 | 232 ± 6 | 223 ± 6*
Sorbitol dehydrogenase (IU/L)
Day 3 | 10 ± 0^b^ | 11 ± 0 | 11 ± 0 | 10 ± 0^b^ | 12 ± 1** | 10 ± 1^b^
Day 22 | 14 ± 1 | 13 ± 1 | 13 ± 0 | 13 ± 1 | 12 ± 1 | 15 ± 1
Week 14 | 16 ± 1 | 16 ± 1 | 14 ± 1 | 15 ± 1 | 15 ± 1 | 22 ± 1**
Female
Hematology
n
Day 3 | 10 | 9 | 10 | 9 | 10 | 9
Day 22 | 8 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 9 | 10 | 10 | 10 | 7
Hematocrit (auto) (%)
Day 3 | 45.4 ± 0.4 | 45.5 ± 0.5 | 45.2 ± 0.6 | 46.3 ± 0.9 | 45.0 ± 0.3 | 46.1 ± 0.8
Day 22 | 47.2 ± 0.7 | 46.1 ± 0.4 | 45.8 ± 0.5 | 46.2 ± 0.3 | 45.5 ± 0.5* | 44.0 ± 0.4**
Week 14 | 45.7 ± 0.5 | 46.3 ± 0.2 | 45.3 ± 0.2 | 45.9 ± 0.4 | 44.2 ± 0.4** | 44.6 ± 0.5*
Manual hematocrit (%)
Day 3 | 45.2 ± 0.6^b^ | 45.3 ± 0.5 | 45.1 ± 0.5 | 45.4 ± 0.8^d^ | 45.1 ± 0.5 | 46.1 ± 0.7
Day 22 | 47.8 ± 0.4 | 46.4 ± 0.4 | 46.6 ± 0.4 | 46.3 ± 0.4* | 46.4 ± 0.5* | 44.3 ± 0.5**
Week 14 | 46.9 ± 0.4 | 47.3 ± 0.3 | 46.6 ± 0.2 | 47.1 ± 0.2 | 45.9 ± 0.3 | 46.3 ± 0.6
Hemoglobin (g/dL)
Day 3 | 14.7 ± 0.1 | 14.7 ± 0.2 | 14.4 ± 0.2 | 14.9 ± 0.3 | 14.5 ± 0.1 | 15.2 ± 0.2
Day 22 | 15.4 ± 0.3 | 15.1 ± 0.1 | 14.9 ± 0.2 | 15.0 ± 0.1 | 14.8 ± 0.2* | 14.1 ± 0.1**
Week 14 | 14.7 ± 0.1 | 14.9 ± 0.1 | 14.7 ± 0.0 | 14.6 ± 0.1 | 14.2 ± 0.1** | 14.0 ± 0.2**
Erythrocytes (10^6^/μL)
Day 3 | 7.97 ± 0.08 | 7.99 ± 0.12 | 7.87 ± 0.08 | 8.08 ± 0.17 | 7.90 ± 0.08 | 8.18 ± 0.11
Day 22 | 8.62 ± 0.14 | 8.37 ± 0.11 | 8.29 ± 0.09* | 8.38 ± 0.07* | 8.17 ± 0.08** | 8.10 ± 0.08**
Week 14 | 8.39 ± 0.10 | 8.51 ± 0.06 | 8.37 ± 0.04 | 8.42 ± 0.06 | 8.19 ± 0.06 | 8.55 ± 0.11
Clinical Chemistry
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 22 | 9 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 7
Total protein (g/dL)
Day 3 | 5.7 ± 0.1^b^ | 5.8 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.5 ± 0.0* | 5.5 ± 0.1*
Day 22 | 6.1 ± 0.1 | 6.1 ± 0.1 | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.6 ± 0.1**
Week 14 | 7.0 ± 0.1 | 7.3 ± 0.1 | 7.2 ± 0.1 | 7.2 ± 0.1 | 7.7 ± 0.1** | 7.9 ± 0.1**
Albumin (g/dL)
Day 3 | 4.1 ± 0.1 | 4.3 ± 0.1 | 4.1 ± 0.1 | 4.2 ± 0.1 | 4.0 ± 0.1 | 4.0 ± 0.1
Day 22 | 4.5 ± 0.1 | 4.4 ± 0.0 | 4.5 ± 0.1 | 4.5 ± 0.0 | 4.5 ± 0.0 | 4.5 ± 0.1
Week 14 | 4.8 ± 0.1 | 5.0 ± 0.1 | 4.9 ± 0.1 | 4.8 ± 0.1 | 5.0 ± 0.1** | 5.1 ± 0.0**
Cholesterol (mg/dL)
Day 3 | 90 ± 2 | 90 ± 3 | 98 ± 2* | 99 ± 2** | 109 ± 3** | 108 ± 4**
Day 22 | 88 ± 8 | 84 ± 4 | 86 ± 1 | 97 ± 2** | 138 ± 2** | 185 ± 4**
Week 14 | 77 ± 2 | 84 ± 3* | 87 ± 1** | 98 ± 2** | 140 ± 3** | 166 ± 6**
Triglycerides (mg/dL)
Day 3 | 95 ± 5 | 85 ± 5 | 78 ± 3 | 86 ± 8 | 102 ± 8 | 209 ± 21**
Day 22 | 72 ± 8 | 67 ± 6 | 54 ± 5 | 56 ± 8 | 61 ± 5 | 94 ± 8
Week 14 | 50 ± 7 | 56 ± 4 | 53 ± 5 | 46 ± 4 | 67 ± 10 | 69 ± 5*
Alanine aminotransferase (IU/L)
Day 3 | 52 ± 1 | 62 ± 3** | 58 ± 2* | 61 ± 2** | 68 ± 2** | 75 ± 3**
Day 22 | 43 ± 2 | 42 ± 2 | 41 ± 1 | 43 ± 1 | 49 ± 1** | 57 ± 3**
Week 14 | 52 ± 2 | 56 ± 4 | 50 ± 2 | 47 ± 2 | 50 ± 2 | 73 ± 4*
Alkaline phosphatase (IU/L)
Day 3 | 510 ± 10 | 555 ± 19 | 532 ± 13 | 541 ± 23 | 508 ± 12 | 488 ± 19
Day 22 | 374 ± 5 | 366 ± 6 | 345 ± 6** | 352 ± 7* | 331 ± 6** | 333 ± 10**
Week 14 | 261 ± 6 | 267 ± 5 | 262 ± 6 | 223 ± 7** | 193 ± 6** | 246 ± 12*
Sorbitol dehydrogenase (IU/L)
Day 3 | 12 ± 1 | 10 ± 1 | 12 ± 1 | 12 ± 1 | 12 ± 1 | 13 ± 2
Day 22 | 11 ± 1 | 11 ± 1 | 11 ± 0 | 15 ± 1* | 18 ± 0** | 16 ± 1**
Week 14 | 13 ± 1 | 14 ± 1 | 13 ± 1 | 15 ± 1 | 16 ± 1** | 29 ± 2**

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 8.

^d^ n = 7.

Small but significant increases in segmented neutrophil counts occurred in 300 and 600 mg/kg males at study termination and could be related to the liver necrosis or lesions in the glandular stomach observed microscopically at 600 mg/kg (Table 3 and Table B-1). Several other significant hematological changes were observed in male and female rats; however, these changes were inconsistent or minimal and thus not considered toxicologically relevant.

Alanine aminotransferase and sorbitol dehydrogenase activities were significantly elevated in several dosed groups of males and females, but most consistently at 600 mg/kg (Table 3 and Table B-1). Alkaline phosphatase (ALP) was significantly decreased in males and females starting on day 22 (Table 3 and Table B-1). In male rats, affected dose groups varied over time with ALP consistently decreased throughout the study in 600 mg/kg males. In females, ALP was decreased in 30 mg/kg or greater groups on day 22 and in the 100 mg/kg or greater groups at week 14. Decreases in serum ALP activity are associated with decreases in food consumption, as the intestinal ALP isoenzyme contributes greatly to total serum ALP activity. While decreased body weight in 600 mg/kg males supports a decrease in food consumption, female body weights were relatively unchanged. Thus, the decreases in ALP may be related to alterations in hepatic enzyme metabolism.

Cholesterol and triglyceride concentrations were significantly elevated in male and female rats in various dose groups (Table 3 and Table B-1). In particular, at week 14, cholesterol was significantly increased in the 100 mg/kg or greater males and in all dosed female groups. Triglycerides were significantly increased in 300 and 600 mg/kg males and 600 mg/kg females at week 14. The reason for the alterations is not known, but may be related to changes in lipid metabolism.

BUN concentrations were significantly increased in 600 mg/kg males on day 3 and 100 mg/kg or greater males on day 22 (Table 3 and Table B-1). At week 14, creatinine, total protein, and albumin concentrations were significantly increased in 300 and 600 mg/kg males and BUN concentration was significantly increased in 600 mg/kg males; these elevations were minimal to mild in magnitude. This particular group of changes is consistent with a decrease in water intake. In females at week 14, total protein and albumin concentrations were significantly increased at 300 and 600 mg/kg; this was also consistent with decreased water intake. The renal nephropathy observed in males was generally minimal and not considered a cause for the mild increases in BUN and creatinine.

The absolute and relative liver weights of 100 mg/kg or greater males and females and the relative liver weight of 30 mg/kg males were significantly increased compared to those of the vehicle controls (Table 4 and Table C-1). The absolute liver weights of 600 mg/kg males and females were 72% and 124% greater than those of the vehicle controls, respectively.

Table 4 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 331 ± 6 | 327 ± 5 | 334 ± 7 | 335 ± 7 | 317 ± 9 | 264 ± 6**
R. Kidney
Absolute | 1.00 ± 0.03 | 0.97 ± 0.02 | 1.04 ± 0.03 | 1.09 ± 0.04* | 1.15 ± 0.04** | 1.09 ± 0.03**
Relative | 3.00 ± 0.05 | 2.97 ± 0.06 | 3.12 ± 0.07 | 3.27 ± 0.09** | 3.62 ± 0.05** | 4.13 ± 0.07**
Liver
Absolute | 12.61 ± 0.26 | 12.44 ± 0.34 | 13.74 ± 0.35 | 14.42 ± 0.44** | 18.97 ± 0.54** | 21.71 ± 0.66**
Relative | 38.07 ± 0.34 | 38.06 ± 0.73 | 41.20 ± 0.97* | 43.04 ± 0.70** | 59.91 ± 0.78** | 82.39 ± 1.68**
Female
n | 10 | 10 | 10 | 10 | 10 | 7
Necropsy body wt | 179 ± 4 | 182 ± 3 | 178 ± 4 | 179 ± 2 | 172 ± 2 | 172 ± 7
R. Kidney
Absolute | 0.64 ± 0.01 | 0.63 ± 0.02 | 0.62 ± 0.02 | 0.65 ± 0.01 | 0.66 ± 0.01 | 0.69 ± 0.02
Relative | 3.55 ± 0.06 | 3.43 ± 0.04 | 3.51 ± 0.09 | 3.61 ± 0.06 | 3.83 ± 0.04** | 4.03 ± 0.08**
Liver
Absolute | 6.55 ± 0.23 | 6.64 ± 0.18 | 6.81 ± 0.12 | 7.88 ± 0.18** | 10.55 ± 0.29** | 14.70 ± 0.50**
Relative | 36.57 ± 0.97 | 36.47 ± 0.65 | 38.33 ± 1.04 | 44.12 ± 1.10** | 61.34 ± 1.58** | 85.76 ± 1.19**

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

The mean absolute and relative kidney weights of 100 mg/kg or greater males were significantly increased compared to the vehicle controls (Table 4 and Table C-1). The absolute kidney weight was highest in 300 mg/kg males and was 15% greater than that of the vehicle controls. The relative kidney weights of 300 and 600 mg/kg females were significantly greater than that of the vehicle control group.

Other differences in organ weights include significantly increased relative heart weight in the 300 and 600 mg/kg males with significantly decreased absolute heart weight in 600 mg/kg males; significantly increased relative lung weight in 600 mg/kg males; and, significantly decreased absolute and relative thymus weight in 600 mg/kg males (Table C-1). These differences are of uncertain toxicologic significance given the decreased body weight and weight gain in the 600 mg/kg males and the lack of treatment-related, histologic lesions in these tissues.

Significant treatment-related, histologic lesions were observed in the liver, glandular stomach, and salivary gland of male and female rats and in the kidney, testis, and epididymis of male rats.

Liver: Treatment-related lesions in the liver included centrilobular hepatocyte hypertrophy, fatty change, and hepatocyte necrosis (Table 5, Table A-1, and Table A-2). The incidences of centrilobular hepatocyte hypertrophy were significantly increased in 300 and 600 mg/kg males and females compared to the vehicle controls. The incidences of fatty change in the liver were significantly increased in 300 and 600 mg/kg males and 600 mg/kg females, and the incidences of hepatocyte necrosis were significantly increased in 600 mg/kg male and females.

Table 5 Incidences of Selected Nonneoplastic Lesions in Rats in the Three-month Gavage Study of Myristicin

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Male
Liver^a^ | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy^b^ | 0 | 0 | 0 | 0 | 10** (2.0)^c^ | 10** (3.0)
Fatty Change | 0 | 0 | 0 | 0 | 10** (1.6) | 10** (1.5)
Hepatocyte, Necrosis | 0 | 0 | 0 | 0 | 0 | 8** (1.0)
Stomach, Glandular | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Atrophy | 0 | 0 | 0 | 0 | 0 | 10** (1.7)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 10** (1.8)
Salivary Glands | 10 | 0 | 0 | 0 | 10 | 10
Submandibular Gland, Depletion Secretory | 0 | – | – | – | 0 | 7** (1.3)
Kidney | 10 | 10 | 10 | 10 | 10 | 10
Renal Tubule, Accumulation, Hyaline Droplet | 0 | 0 | 0 | 0 | 10** (1.0) | 10** (1.9)
Nephropathy | 10 (1.0) | 10 (1.0) | 9 (1.0) | 10 (1.0) | 10 (1.0) | 10 (1.8)
Female
Liver | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy | 0 | 0 | 0 | 0 | 10** (2.0) | 7** (3.0)
Fatty Change | 0 | 0 | 0 | 0 | 1 (1.0) | 10** (1.9)
Hepatocyte, Necrosis | 0 | 0 | 0 | 0 | 0 | 6** (1.2)
Stomach, Glandular | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Atrophy | 0 | 0 | 0 | 0 | 5** (1.0) | 7** (1.7)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 7** (1.4)
Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 2 (1.0)
Salivary Glands | 10 | 0 | 0 | 10 | 10 | 10
Submandibular Gland, Depletion Secretory | 0 | – | – | 0 | 10** (1.5) | 7** (3.0)

** Significantly different (P ≤ 0.01) from the vehicle control group by the Fisher exact test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Microscopically, hepatocyte hypertrophy was mild to moderate in severity and characterized by the presence of enlarged centrilobular hepatocytes with eosinophilic granular cytoplasm (Figure 5 and Figure 6). At 300 mg/kg, hepatocyte hypertrophy was generally restricted to the centrilobular zone, but at 600 mg/kg, it often extended into the midzonal region or throughout the lobule. Increased liver weights and grossly observed liver enlargement corresponded microscopically with centrilobular hepatocyte hypertrophy and fatty change in 300 and 600 mg/kg male and female rats. Fatty change in the liver was minimal to mild in severity and characterized by numerous, variably sized (macrovesicular and microvesicular) discrete, clear vacuoles within the cytoplasm of scattered hepatocytes (Figure 5 and Figure 6).

Hepatocyte necrosis was generally minimal in severity and characterized by single or, less often, small clusters of hepatocytes with condensed, hypereosinophilic cytoplasm that had shrunken or karyorrhectic nuclei, sometimes associated with low numbers of neutrophils and mononuclear inflammatory cells. Additionally, a single early death 600 mg/kg female was diagnosed with mild necrosis in the liver, which differed from the diagnosis of hepatocyte necrosis in that it was characterized by multiple larger, discrete foci of coagulative necrosis.

Glandular Stomach: Treatment-related lesions in the glandular stomach included epithelium atrophy and hyperplasia in males and females and epithelium necrosis in females (Table 5, Table A-1, and Table A-2). The incidences of epithelium atrophy were significantly increased in 600 mg/kg males and in 300 and 600 mg/kg females compared to the vehicle controls. The incidences of epithelium hyperplasia were significantly increased in the 600 mg/kg males and females. Epithelium necrosis of the glandular stomach was observed in two 600 mg/kg females, which died on day 4 of the study. Although this increase was not statistically significant, the necrosis of the glandular stomach in these females is considered to be treatment related.

Microscopically, epithelium atrophy ranged from minimal to mild in severity and was characterized by decreased cellularity and height of the mucosa due to nearly complete or complete loss of chief and parietal cells with single cell death of both of these cell types (Figure 7 and Figure 8). In general, there was slight distortion of glands that remained and increased prominence of stroma between the glands. There were few granulocytes and mononuclear cells scattered within the lamina propria extending between and accumulating in gastric glands. Epithelium atrophy in 300 mg/kg females differed from that in 600 mg/kg males and females in that there was only a decrease in the number of chief cells and the remaining glandular epithelium appeared histologically normal. Epithelium atrophy was accompanied by minimal to mild epithelium hyperplasia within the overall atrophic, thinned mucosal epithelium. Epithelium hyperplasia was characterized by small, scattered foci with increased numbers of epithelial cells with basophilic cytoplasm, especially mucus neck cells, and increased numbers of mitotic figures (Figure 8). Epithelium necrosis of the glandular stomach was seen as single cell necrosis of chief cells and parietal cells with accumulation of desquamated epithelial cells in dilated gastric glands.

Salivary Gland: The incidences of secretory depletion in the submandibular gland were significantly increased in the 600 mg/kg males and 300 and 600 mg/kg females compared to the vehicle controls (Table 5, Table A-1, and Table A-2). Microscopically, this lesion was characterized by a decrease in the number of cytoplasmic zymogen granules within the epithelial cells of the granular convoluted ducts (Figure 9) as compared to the normal salivary gland (Figure 10). In males, the lesion was of minimal to mild severity and also encompassed disorganization of the epithelial cells of the granular convoluted ducts. In females, the lesion was of minimal to moderate severity, and the granular convoluted ducts were often severely shrunken due to lack of cytoplasm.

Kidney: Treatment-related lesions in the kidney of male rats included renal tubule hyaline droplet accumulation and a slight increase in the severity of nephropathy (Table 5 and Table A-1). The incidences of renal tubule hyaline droplet accumulation were significantly increased in the 300 and 600 mg/kg males compared to the vehicle controls. Hyaline droplet accumulation was present in all 300 and 600 mg/kg males and increased in severity from minimal at 300 mg/kg to mild at 600 mg/kg. Nephropathy, which was minimal in severity in vehicle control, 10, 30, 100, and 300 mg/kg males, increased to generally mild in severity in 600 mg/kg males.

Hyaline droplet accumulation was observed in the renal tubule epithelium of the proximal convoluted tubules. In contrast to the fine, round, cytoplasmic droplets characteristic of the vehicle control kidneys (Figure 11), the cytoplasmic droplets in the 300 and 600 mg/kg males were increased in number and size and were irregularly angular and more pleomorphic (Figure 12). There was also loss of the droplet-congested cells that are typical of the control kidneys. Although evident in the H&E-stained sections, droplets in treated animals were more prominent upon staining with the Mallory-Heidenhain method or ultraviolet illumination, suggestive of accumulation of α_2u_-globulin. Increases in kidney weights corresponded microscopically to the accumulation of hyaline droplets in the 300 and 600 mg/kg males. There was a slight increase in the severity (exacerbation) of nephropathy in the 600 mg/kg males, based upon an increase in the number of foci of regenerating tubules. Microscopically, nephropathy was consistent with the early stages of chronic progressive nephropathy typically observed in rats.

Male Reproductive System: Treatment-related histologic lesions in the male reproductive system included germinal epithelium degeneration and elongated spermatid retention in seminiferous tubules of the testis and exfoliated germ cells in the duct lumina of the epididymis (Table 6 and Table A-1). In the testis, the incidences of germinal epithelium degeneration and elongated spermatid retention in 600 mg/kg males were significantly increased compared to those of the vehicle control group; the severities of both lesions in this dose group were also greater than the severities found in the vehicle control group. In the epididymis, the incidence of exfoliated germ cell was significantly increased in 600 mg/kg males compared to that in the vehicle controls.

Table 6 Reproductive System Parameters of Male Rats in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
n | 10 | – | – | 10 | 10 | 10
L. Testis Weight | 1.4464 ± 0.0217 | – | – | 1.4943 ± 0.0226 | 1.5092 ± 0.0317 | 1.4106 ± 0.0220
L. Cauda Epididymis Weight | 0.1365 ± 0.0033 | – | – | 0.1387 ± 0.0028 | 0.1292 ± 0.0045 | 0.1070 ± 0.0031**
L. Epididymis Weight | 0.4090 ± 0.0071 | – | – | 0.4104 ± 0.0038 | 0.4008 ± 0.0096 | 0.3444 ± 0.0080**
Sperm (10^6^/cauda epididymis) | 89.37 ± 5.49 | – | – | 88.63 ± 4.42 | 79.11 ± 4.47 | 67.63 ± 3.18**
Epididymis^b^ | 10 | 10 | 10 | 10 | 10 | 10
Exfoliated Germ Cell^c^ | 1 (1.0)^d^ | 3 (1.3) | 1 (1.0) | 2 (1.0) | 4 (2.3) | 10^▲▲^ (1.5)
Testes | 10 | 10 | 10 | 10 | 10 | 10
Germinal Epithelium, Degeneration | 5 (1.4) | 5 (2.2) | 3 (1.3) | 6 (1.3) | 8 (1.6) | 10^▲^ (2.3)
Elongated Spermatid, Retention | 5 (1.0) | 3 (1.0) | 0 | 1 (1.0) | 6 (1.0) | 10^▲^ (1.4)

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ (tissue weights) or Shirley’s (sperm measurements) test.

^▲^Significantly different from the vehicle control group (P ≤ 0.05) by the Fisher exact test.

^▲▲^P ≤ 0.01.

^a^ Tissue weights and sperm data are presented as mean ± standard error. Tissue weights and sperm data were not evaluated for 10 and 30 mg/kg males.

^b^ Number of animals with tissue examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Microscopically, germinal epithelium degeneration was mild to moderate and characterized by a decrease and/or disorganization or vacuolization of the germinal epithelial layers (Figure 13 and Figure 14). Elongated spermatid retention in the testis was minimal to mild and characterized by the presence of mature elongated spermatids at the luminal surface or within the germinal epithelium of Stage IX and X seminiferous tubules (Figure 15). Exfoliated germ cells in the epididymis were characterized by minimal to mild increases in the numbers of rounded germ cells and cellular debris in the epididymal duct lumina, primarily in the tail of the epididymis, exceeding the numbers normally observed in the epididymis of vehicle control animals (Figure 16).

Male rats in the 600 mg/kg dose group had significantly decreased absolute left cauda and left epididymis weights and mean total number of sperm per cauda epididymis compared to those of the vehicle controls (approximately 22%, 16%, and 24% lower, respectively) (Table 6 and Table D-1). Myristicin exposure via gavage exhibited the potential to be a reproductive toxicant in male F344/NTac rats.

Other Findings: In the lung of females, significantly increased incidences of chronic active inflammation occurred at 30, 100, and 300 mg/kg (2/10, 6/10, 7/10, 7/10, 10/10, 5/10), and significantly increased incidences of alveolus infiltration cellular histiocyte occurred in 30 mg/kg or greater females (2/10, 5/10, 8/10, 8/10, 9/10, 7/10) (Table A-2). The lung lesions, which also were present in male rats, were characterized by focally extensive to multifocal infiltrates of lymphohistiocytic cells, resulting in alveolar septal wall thickening (i.e., interstitial pneumonia) accompanied by prominent perivascular “cuffing” of pulmonary veins by dense infiltrates of primarily lymphocytes. Histiocytic alveolus infiltration was characterized by the presence of intra-alveolar clusters of large, foamy macrophages. These lung changes are consistent with mild infection with Pneumocystis carinii,^87^ which was not a recognized etiologic agent in rats at the time of the study. In general, the relationship of these changes to exposure is uncertain.

## Three-month Study in Mice

All mice survived to the end of the study (Table 7). The final mean body weights and mean body weight gains of 300 and 600 mg/kg males and females were significantly less than those of the vehicle control groups (Table 7 and Figure 4). The final mean body weights of 600 mg/kg males and females were 24% and 16% less, respectively, than those of vehicle controls. Clinical observations included thinness in one 300 mg/kg male and one 600 mg/kg female and ruffled fur in one 300 mg/kg male and one 600 mg/kg male. As seen in rats, the livers of all the 300 and 600 mg/kg male and female mice were also enlarged at scheduled termination. A few treated mice had white or tan foci in the forestomach.

Table 7 Survival and Body Weights of Mice in the Three-month Gavage Study of Myristicin^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 22.7 ± 0.4 | 38.8 ± 1.2 | 16.1 ± 1.0
10 | 10/10 | 22.6 ± 0.3 | 38.1 ± 1.1 | 15.6 ± 0.9 | 98
30 | 10/10 | 22.6 ± 0.2 | 38.3 ± 0.8 | 15.7 ± 0.7 | 99
100 | 10/10 | 22.6 ± 0.2 | 37.7 ± 0.9 | 15.1 ± 0.8 | 97
300 | 10/10 | 22.8 ± 0.4 | 34.2 ± 1.1** | 11.2 ± 0.8** | 88
600 | 10/10 | 22.7 ± 0.3 | 29.3 ± 0.6** | 6.6 ± 0.4** | 76
Female
0 | 10/10 | 17.9 ± 0.2 | 28.3 ± 0.8 | 10.4 ± 0.6
10 | 10/10 | 18.0 ± 0.2 | 31.0 ± 0.8 | 12.9 ± 0.7 | 109
30 | 10/10 | 17.8 ± 0.2 | 29.1 ± 1.0 | 11.3 ± 0.9 | 103
100 | 10/10 | 18.3 ± 0.3 | 27.2 ± 0.6 | 8.9 ± 0.4 | 96
300 | 10/10 | 17.9 ± 0.4 | 25.3 ± 0.3** | 7.4 ± 0.3** | 89
600 | 10/10 | 17.8 ± 0.3 | 23.9 ± 0.4** | 6.2 ± 0.4** | 85

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 4

Growth Curves for Mice Administered Myristicin by Gavage for Three Months

The erythrocyte counts were significantly decreased in the 100 mg/kg and greater males, and the automated hematocrit value was significantly decreased in 600 mg/kg males (Table 8 and Table B-2). These erythron changes were mild and not observed in the females and, therefore, their toxicologic significance is uncertain. It is plausible that the mild decrease in the erythron was due to erythroid suppression secondary to the chronic inflammation observed in the stomach, which is supported by the changes in the leukon (increased leukocyte counts). Leukocyte counts were significantly increased in 300 and 600 mg/kg males and 600 mg/kg females. In addition, segmented neutrophil counts were significantly increased in 300 and 600 mg/kg males and females. Also, the lymphocyte count was significantly increased in 600 mg/kg males and the monocyte count was significantly increased in 600 mg/kg females. The increase in the leukon is consistent with the chronic inflammation observed in the stomach.

Table 8 Selected Hematology Data for Mice in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Male
n | 10 | 9 | 10 | 9 | 10 | 10
Hematocrit (auto) (%) | 50.1 ± 0.6 | 50.0 ± 0.7 | 49.7 ± 0.5 | 48.2 ± 0.3 | 49.1 ± 0.6 | 48.0 ± 0.6*
Erythrocytes (10^6^/µL) | 10.72 ± 0.11 | 10.72 ± 0.18 | 10.70 ± 0.11 | 10.25 ± 0.06** | 10.48 ± 0.14* | 10.40 ± 0.15*
Leukocytes (10^3^/µL) | 5.68 ± 0.22 | 4.61 ± 0.26 | 5.87 ± 0.84 | 5.61 ± 0.26 | 7.36 ± 0.39* | 8.86 ± 0.60**
Segmented neutrophils (10^3^/µL) | 0.80 ± 0.04 | 0.74 ± 0.10 | 0.85 ± 0.09 | 0.93 ± 0.07 | 1.24 ± 0.14** | 2.12 ± 0.30**
Lymphocytes (10^3^/µL) | 4.66 ± 0.19 | 3.68 ± 0.17 | 4.83 ± 0.72 | 4.48 ± 0.21 | 5.80 ± 0.29 | 6.36 ± 0.36*
Monocytes (10^3^/µL) | 0.10 ± 0.02 | 0.08 ± 0.02 | 0.09 ± 0.02 | 0.08 ± 0.02 | 0.13 ± 0.02 | 0.18 ± 0.04
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Leukocytes (10^3^/µL) | 5.16 ± 0.53 | 3.79 ± 0.12 | 4.16 ± 0.24 | 5.46 ± 0.27 | 6.12 ± 0.35 | 7.75 ± 0.76*
Segmented neutrophils (10^3^/µL) | 0.56 ± 0.08 | 0.52 ± 0.05 | 0.61 ± 0.08 | 0.72 ± 0.08 | 0.89 ± 0.08** | 1.43 ± 0.23**
Lymphocytes (10^3^/µL) | 4.40 ± 0.47 | 3.19 ± 0.11 | 3.40 ± 0.19 | 4.52 ± 0.18 | 5.04 ± 0.32 | 5.97 ± 0.67
Monocytes (10^3^/µL) | 0.07 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.11 ± 0.03 | 0.09 ± 0.01 | 0.16 ± 0.02**

* Significantly different (P ≤ 0.05) from the vehicle control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are given as mean ± standard error. Statistical tests were performed on unrounded data.

The absolute and relative liver weights of males administered 100 mg/kg or greater and all dosed groups of females were significantly greater than those of the vehicle control groups (the absolute liver weights of 600 mg/kg males and females were 75% and 128% greater than those of the vehicle control groups, respectively) (Table 9 and Table C-2). Other changes in organ weights included significantly increased relative heart weight in 300 and 600 mg/kg males with significantly decreased absolute heart weight in 600 mg/kg males; significantly increased relative lung weight in 600 mg/kg males; and, significantly decreased absolute and relative thymus weight in 600 mg/kg males (Table C-2). These findings are of uncertain toxicologic significance given the decreased body weight and weight gain in the 600 mg/kg males and the lack of treatment-related lesions in these tissues. Significant histologic lesions were observed in the liver, nose, and stomach of male and female mice.

Table 9 Liver Weights and Liver Weight-to-Body Weight Ratios for Mice in the Three-month Gavage Study of Myristicin

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 38.8 ± 1.2 | 38.1 ± 1.1 | 38.3 ± 0.8 | 37.7 ± 0.9 | 34.2 ± 1.1** | 29.3 ± 0.6**
Liver
Absolute | 1.54 ± 0.05 | 1.57 ± 0.05 | 1.58 ± 0.04 | 1.73 ± 0.04** | 2.32 ± 0.06** | 2.69 ± 0.06**
Relative | 39.67 ± 0.46 | 41.18 ± 0.90 | 41.09 ± 0.47 | 45.97 ± 0.54** | 67.94 ± 1.05** | 91.64 ± 0.79**
Female
Necropsy body wt | 28.3 ± 0.8 | 31.0 ± 0.8 | 29.1 ± 1.0 | 27.2 ± 0.6 | 25.3 ± 0.3** | 23.9 ± 0.4**
Liver
Absolute | 1.09 ± 0.02 | 1.29 ± 0.04** | 1.21 ± 0.03** | 1.27 ± 0.04** | 1.76 ± 0.03** | 2.49 ± 0.06**
Relative | 38.77 ± 0.54 | 41.52 ± 0.74* | 41.77 ± 0.56* | 46.64 ± 0.97** | 69.63 ± 1.22** | 103.96 ± 1.23**

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

** P ≤ 0.01.

^a^ Liver weights (absolute weights) and body weights are given in grams; liver-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Liver: Treatment-related lesions in the liver included fatty change, centrilobular hepatocyte hypertrophy, and hepatocyte necrosis, as also seen in rats; additionally, oval cell hyperplasia, clear cell foci, and basophilic foci were observed in mice (Table 10, Table A-3, and Table A-4). The incidences of fatty change were significantly increased in 100 mg/kg or greater males and in 600 mg/kg females compared to those in the respective vehicle controls. The incidences of centrilobular hepatocyte hypertrophy were significantly increased in 300 and 600 mg/kg males and 100 mg/kg and greater females. The incidences of hepatocyte necrosis and oval cell hyperplasia were significantly increased in 600 mg/kg males and in 300 and 600 mg/kg females. A few incidences of clear cell foci were observed in 300 and 600 mg/kg females, and one female each in the 30 and 300 mg/kg groups had basophilic foci.

Table 10 Incidences of Selected Nonneoplastic Lesions in Mice in the Three-month Gavage Study of Myristicin

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Male
Liver^a^ | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy^b^ | 0 | 0 | 0 | 0 | 10** (2.9)^c^ | 10** (3.0)
Fatty Change | 0 | 0 | 0 | 8** (1.0) | 5* (1.0) | 10** (1.2)
Hepatocyte, Necrosis | 0 | 0 | 0 | 0 | 1 (1.0) | 10** (1.0)
Oval Cell, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 10** (1.0)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Atrophy | 0 | 0 | 0 | 0 | 10** (1.0) | 10** (2.0)
Nerve, Atrophy | 0 | 0 | 0 | 0 | 8** (1.0) | 10** (2.0)
Glands, Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 7** (1.0)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 0 | 0 | 0 | 0 | 2 (1.0) | 9** (1.3)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 4 (1.0) | 5 (1.4) | 1 (1.0) | 5 (1.0) | 10** (1.2) | 10** (2.1)
Respiratory Epithelium, Vacuolization, Cytoplasmic | 1 (1.0) | 1 (1.0) | 0 | 0 | 0 | 6* (1.3)
Stomach, Glandular | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Atrophy | 0 | 0 | 0 | 0 | 0 | 10** (1.7)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 10** (2.0)
Stomach, Forestomach | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Chronic | 0 | 0 | 0 | 0 | 2 (1.0) | 4* (3.5)
Ulcer | 0 | 0 | 0 | 0 | 0 | 2 (2.5)
Epithelium, Hyperkeratosis | 0 | 0 | 0 | 0 | 2 (1.0) | 3 (3.7)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 1 (2.0) | 3 (4.0)
Epithelium, Inflammation, Suppurative | 0 | 0 | 0 | 0 | 0 | 4* (3.5)
Female
Liver | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy | 0 | 0 | 0 | 10** (2.0) | 10** (3.0) | 10** (3.0)
Fatty Change | 0 | 0 | 0 | 0 | 0 | 10** (1.0)
Hepatocyte, Necrosis | 0 | 0 | 0 | 1 (1.0) | 10** (1.0) | 10** (1.0)
Oval Cell, Hyperplasia | 0 | 0 | 0 | 0 | 10** (1.0) | 10** (2.4)
Clear Cell Focus | 0 | 0 | 0 | 0 | 3 | 2
Basophilic Focus | 0 | 0 | 1 | 0 | 1 | 0
Nose | 10 | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Atrophy | 0 | 0 | 0 | 0 | 10** (1.0) | 10** (2.0)
Nerve, Atrophy | 0 | 0 | 0 | 0 | 9** (1.2) | 10** (2.0)
Glands, Olfactory Epithelium Hyperplasia | 0 | 0 | 0 | 0 | 0 | 10** (1.0)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 0 | 1 (1.0) | 0 | 3 (1.0) | 8** (1.0) | 10** (1.9)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 5 (1.2) | 3 (1.7) | 1 (1.0) | 7 (1.4) | 10* (2.5) | 10* (2.7)
Respiratory Epithelium, Vacuolization, Cytoplasmic | 0 | 0 | 0 | 0 | 2 (2.0) | 4* (2.0)
Stomach, Glandular | 10 | 10 | 10 | 10 | 10 | 10
Epithelium, Atrophy | 0 | 0 | 0 | 0 | 0 | 10** (1.2)
Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 10** (1.6)
Stomach, Forestomach | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Chronic | 0 | 0 | 2 (3.0) | 1 (3.0) | 1 (2.0) | 3 (3.7)
Ulcer | 0 | 0 | 0 | 1 (1.0) | 0 | 2 (3.0)
Epithelium, Hyperkeratosis | 0 | 0 | 2 (3.0) | 1 (4.0) | 1 (2.0) | 3 (4.0)
Epithelium, Hyperplasia | 0 | 0 | 2 (2.0) | 1 (4.0) | 1 (2.0) | 3 (3.7)
Epithelium, Inflammation, Suppurative | 0 | 0 | 2 (2.0) | 1 (3.0) | 0 | 3 (3.7)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Microscopically, fatty change in mice was generally of minimal severity and was similar to that observed in rats (Figure 17 and Figure 18). Both numerous, small (microvesicular) intracytoplasmic vacuoles, generally in hypertrophied hepatocytes, and fewer, discrete, large (macrovesicular) vacuoles, generally in non-hypertrophied periportal hepatocytes, were present.

Hepatocyte hypertrophy was mild to moderate in severity, and in general, was morphologically similar to that observed in rats in both appearance and distribution. Affected hepatocytes were swollen with increased amounts of granular eosinophilic cytoplasm; often there was variation in nuclear size and increased numbers of mitotic figures (Figure 17 and Figure 18). In 300 and 600 mg/kg males and 100 mg/kg females, hypertrophied hepatocytes were mainly centrilobular or extended into the midzonal region, whereas in 300 and 600 mg/kg females, they occupied the entire lobule, resulting in obscured hepatic cords. Elevated liver weights and gross liver enlargement corresponded microscopically with centrilobular hepatocyte hypertrophy in 300 and 600 mg/kg male and female mice. Hepatocyte necrosis was seen as individual swollen or shrunken hepatocytes with hypereosinophilic cytoplasm and shrunken or fragmented nuclei, often accompanied by inflammatory cell infiltrates.

Oval cell hyperplasia was of minimal to mild severity and consisted of linear proliferative arrays, often along sinusoids, of small, oval, slightly basophilic cells with round to oval basophilic nuclei (Figure 18). Clear cell focus was seen as a discrete cluster of diffusely vacuolated hepatocytes clearly distinct from but not compressing the adjacent hepatic parenchyma. Basophilic focus was similar but composed of hepatocytes with basophilic cytoplasm.

Nose: Treatment-related lesions occurred in the nose of mice, unlike in rats, and included epithelial atrophy, nerve atrophy, glands hyperplasia, and hyaline droplet accumulation of the olfactory epithelium and hyaline droplet accumulation and cytoplasmic vacuolization of the respiratory epithelium (Table 10, Table A-3, and Table A-4). The incidences of olfactory epithelium atrophy and nerve atrophy in 300 and 600 mg/kg males and females were significantly greater than those in the vehicle controls. Both olfactory epithelium atrophy and nerve atrophy generally increased in severity from minimal at 300 mg/kg to mild at 600 mg/kg in both sexes (Table 10). The incidences of glands hyperplasia of the olfactory epithelium in 600 mg/kg males and females and hyaline droplet accumulation of the olfactory epithelium in 600 mg/kg males and 300 and 600 mg/kg females were significantly increased. In the respiratory epithelium, the incidences of hyaline droplet accumulation in 300 and 600 mg/kg males and females and cytoplasmic vacuolization in 600 mg/kg males and females were significantly increased.

Microscopically, olfactory epithelium atrophy was minimal to mild in severity and characterized by decreased cellularity and height of the olfactory epithelium, most commonly along the dorsomedial aspect of the Level II and III sections of the nose and sometimes scattered along turbinates in the Level III sections (Figure 19 and Figure 20). At the junction of the atrophied epithelium with the more normal adjacent olfactory epithelium, the epithelium was disorganized and lined by numerous shrunken epithelial cells with eosinophilic, granular cytoplasm and irregularly shaped, condensed nuclei. Olfactory epithelium atrophy was accompanied by atrophy of the olfactory nerves, characterized by shrinkage of the nerve axons in the lamina propria subjacent to the atrophied olfactory epithelium (Figure 21 and Figure 22). Hyperplasia of the glands of the olfactory epithelium was minimal in severity and characterized by increased prominence and cellularity of Bowman’s glands in the lamina propria underlying the atrophic olfactory epithelium; in some animals, the glandular epithelial cells were also hypertrophied (Figure 21 and Figure 22).

Hyaline droplet accumulation occurred in both the olfactory and respiratory epithelia, and was characterized by accumulation of brightly eosinophilic, globular, homogeneous material that expanded the cytoplasm (Figure 23 and Figure 24).

Respiratory epithelium cytoplasmic vacuolization was minimal to mild in severity and characterized by the presence of expansive clear spaces in the apical cytoplasm of respiratory epithelium along the nasal septum in the Level II sections of the nose in treated mice that had concomitant hyaline droplet accumulation (Figure 25).

Stomach (Glandular and Forestomach): The incidences of atrophy and hyperplasia in the epithelium of the glandular stomach were significantly increased in 600 mg/kg males and females compared to the vehicle controls (Table 10, Table A-3, and Table A-4). Epithelium atrophy and epithelium hyperplasia in the glandular stomach of mice were morphologically similar to that observed in rats. Rarely, the replicative, hyperplastic population of epithelial cells formed dilated or irregularly formed glands with accumulations of desquamated cells. Low numbers of neutrophils and mononuclear cells were present within the lamina propria and extending between the gastric glands.

In the forestomach, low incidences of lesions occurred in 300 and 600 mg/kg males and in 30 mg/kg or greater females and included epithelial hyperplasia and hyperkeratosis, ulcers, chronic inflammation, and epithelial suppurative inflammation (Table 10, Table A-3, and Table A-4). In general, these lesions co-occurred in the same animals. The incidences of chronic inflammation and epithelial suppurative inflammation in 600 mg/kg males were significantly increased compared to those of the vehicle controls. However, the incidences of these forestomach lesions were not statistically significant in females. Severities for these forestomach lesions were highest in the 600 mg/kg groups of males and females. These lesions likely corresponded to the white or tan foci observed grossly in the forestomachs of a few treated mice. Similar lesions were not observed in the forestomachs of rats. Chronic inflammation was seen microscopically as mixed inflammatory cell infiltrates of mainly mononuclear cells in the lamina propria and submucosa, and chronic inflammation was in some cases associated with ulceration. Epithelial suppurative inflammation was characterized by multifocal pustule-like accumulations of neutrophils within the superficial epithelium of the forestomach and was also sometimes associated with ulceration.

Male Reproductive System: Male mice in the 600 mg/kg dose group had significantly lower absolute left cauda, left epididymis, and left testis weights (approximately 21%, 18%, and 7% lower, respectively) compared to those of the vehicle controls; however, the high dose mice weighed 24% less than the vehicle control mice, so these organ weight changes are considered secondary to body weight (Table 11 and Table D-2). Reproductive organ weight changes were not accompanied by any significant histopathologic lesions (Table A-3). There were also no changes in spermatid counts/mg of cauda, spermatid heads/testis or per mg testis, or sperm motility in the exposed groups as compared to the vehicle control group (Table D-2).

Table 11 Selected Reproductive Tissue Weights for Male Mice in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 100 mg/kg | 300 mg/kg | 600 mg/kg
n | 10 | 10 | 10 | 10
L. Cauda Epididymis Weight | 0.0132 ± 0.0006 | 0.0138 ± 0.0007 | 0.0138 ± 0.0007 | 0.0104 ± 0.0006**
L. Epididymis Weight | 0.0409 ± 0.0012 | 0.0414 ± 0.0007 | 0.0401 ± 0.0009 | 0.0337 ± 0.0010**
L. Testis Weight | 0.1118 ± 0.0016 | 0.1110 ± 0.0018 | 0.1147 ± 0.0014 | 0.1045 ± 0.0010**

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ or Dunnett’s test.

^a^ Reproductive tissue weights are presented as mean ± standard error. Reproductive tissues were not weighed for 10 or 30 mg/kg males.

## Genetic Toxicology

Myristicin (3.3 to 833 µg/plate) was not mutagenic in Salmonella typhimurium strains TA97, TA98, TA100, or TA1535, when tested with or without exogenous metabolic activation provided by Aroclor 1254-induced rat or hamster liver S9 and cofactors (Table E-1). The highest testable dose in the absence of S9 was 217 µg/plate; with S9, doses up to 833 µg/plate were able to be tested.

In rats, the reticulocyte population is the only red blood cell population that can be accurately assessed for micronucleus frequency in peripheral blood due to efficient splenic scavenging of damaged erythrocytes soon after they emerge from the bone marrow. In both sexes of rats in the 3-month study, the frequencies of micronucleated reticulocytes (polychromatic erythrocytes; PCEs) were significantly increased at 600 mg/kg (Table E-2). The effect at this dose resulted in statistically significant trend tests for both sexes, and results were judged to be positive for both male and female rats. In addition, and in contrast with what was seen in the mice, myristicin appeared to stimulate erythropoiesis in male and female rats, with significant, dose-dependent increases in the percent PCEs observed in both sexes. It should be noted that stimulation of erythropoiesis may, in some instances, result in elevated levels of micronucleated red blood cells due to an increase in mitotic errors associated with rapid cell division, although in in vivo micronucleus studies conducted by the National Toxicology Program, no consistent association between increases in percent PCEs and increases in micronuclei has been observed.

No increases in the frequency of micronucleated erythrocytes (either immature or mature) were seen in the peripheral blood of male or female mice in the 3-month study (Table E-3). Significant, dose-dependent decreases in the percentage of PCEs in peripheral blood seen in both sexes of mice suggest that the bone marrow was a target for myristicin-induced cytotoxicity.

Figure 5

Normal Liver in a Vehicle Control Female F344/NTac Rat at Three Months in the Gavage Study of Myristicin (H&E)

Note the uniform size of hepatocytes. CV = central vein.

Figure 6

Centrilobular Hepatocyte Hypertrophy and Fatty Change in the Liver of a Female F344/NTac Rat Administered 600 Mg/Kg Myristicin by Gavage for Three Months (H&E)

Note that hepatocytes centered around central veins (CV) are enlarged with lightly eosinophilic, granular cytoplasm, with some containing vacuoles consistent with lipid accumulation. Occasional hepatocytes are necrotic (arrow). Compare to the normal liver in Figure 5 at the same magnification.

Figure 7

Normal Glandular Stomach in a Vehicle Control Female F344/NTac Rat at Three Months in the Gavage Study of Myristicin (H&E)

Note the orderly progression of the epithelial cells in the gastric glands with midzonal, eosinophilic parietal (P) cells and basal, dark staining chief cells (C).

Figure 8

Epithelium Atrophy and Epithelium Hyperplasia in the Glandular Stomach of a Female F344/NTac Rat Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Epithelium atrophy is demonstrated by an overall decrease in mucosal height due to loss of many of the parietal (P) and chief cells (C), and the glands have lost the orderly progression in cell types. There is also hyperplasia of some other glandular epithelial cells, especially mucous neck cells (H). Compare to the normal glandular stomach in Figure 7 at the same magnification.

Figure 9

Secretory Depletion in the Submandibular Salivary Gland of a Male F344/NTac Rat Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Note the decreased number of eosinophilic, cytoplasmic granules in granular convoluted ducts when compared to the normal submandibular salivary gland in Figure 10.

Figure 10

Normal Submandibular Salivary Gland in a Vehicle Control Male F344/NTac Rat at Three Months in the Gavage Study of Myristicin (H&E)

Figure 11

Normal Kidney in a Vehicle Control Male F344/NTac Rat at Three Months in the Gavage Study of Myristicin Showing the Normal Background Level of Uniformly Fine, Eosinophilic (Hyaline) Droplets within the Cytoplasm of Renal Tubule Epithelial Cells (H&E)

Figure 12

Hyaline Droplet Accumulation in the Kidney of a Male F344/NTac Rat Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Compared to the normal kidney in Figure 11, there are larger, variably-sized, round to irregularly angular eosinophilic (hyaline) droplets within the cytoplasm of several renal tubule epithelial cells.

Figure 13

Germinal Epithelium Degeneration in Several Seminiferous Tubules of the Testis of a Male F344/NTac Rat Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Figure 14

Higher Magnification of Germinal Epithelium Degeneration in the Testis of a Male F344/NTac Rat Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

An early-stage seminiferous tubule displays disorganization of the germinal epithelium, depletion of round and elongating spermatids, and vacuolation.

Figure 15

Spermatid Retention in a Late-Stage Seminiferous Tubule in the Testis of a Male F344/NTac Rat Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Several mature, elongated step 19 spermatids are retained within the germinal epithelium near the luminal surface (arrows) as well as within the basal cytoplasm (circles).

Figure 16

Exfoliated Germ Cells in the Duct Lumina of the Epididymis of a Male F344/NTac Rat Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Figure 17

Normal Liver in a Vehicle Control Female B6C3F1/N Mouse at Three Months in the Gavage Study of Myristicin (H&E)

Note the uniform size of hepatocytes and distinct sinusoids.

Figure 18

Centrilobular Hepatocyte Hypertrophy, Fatty Change, and Oval Cell Hyperplasia in the Liver of a Female B6C3F1/N Mouse Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Hepatocytes are enlarged with lightly eosinophilic, granular cytoplasm, with some containing vacuoles consistent with lipid accumulation. Oval cell hyperplasia is seen as proliferative arrays of small, oval, basophilic cells along sinusoids (black arrows). Occasional hepatocytes are necrotic (white arrow). Compare to the normal liver in Figure 17 at the same magnification.

Figure 19

Low Magnification of a Normal Level III Section of the Nose in a Vehicle Control Female B6C3F1/N Mouse at Three Months in the Gavage Study of Myristicin (H&E)

The thickness of the olfactory epithelium is uniform.

Figure 20

Low Magnification of a Level III Section of the Nose in a Female B6C3F1/N Mouse Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

The olfactory epithelium is atrophied and thinned along the dorsomedial aspect (arrows). Compare to the normal Level III section of the nose in Figure 19 at the same magnification.

Figure 21

Normal Olfactory Epithelium in a Vehicle Control Female B6C3F1/N Mouse at Three Months in the Gavage Study of Myristicin (H&E)

Higher magnification of the dorsal meatus of the nasal cavity from the Level III section shown in Figure 19. The olfactory epithelium (OE) is thick, and nerve bundles (N) are prominent in the underlying lamina propria.

Figure 22

Olfactory Epithelium Atrophy, Nerve Atrophy, and Glands Hyperplasia of the Olfactory Epithelium in a Female B6C3F1/N Mouse Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Higher magnification of the dorsal meatus of the nasal cavity from the Level III section shown in Figure 20. Compared to Figure 21, the olfactory epithelium (OE) is thinned and less cellular, and the olfactory nerves (N) in the lamina propria are decreased in size and number. In contrast, the Bowman’s glands (arrows) in the lamina propria are increased in size and number in the treated mouse compared to the vehicle control mouse in Figure 21.

Figure 23

Normal Respiratory Epithelium (arrows) Along the Nasal Septum in a Level II Section of the Nose from a Vehicle Control Female B6C3F1/N Mouse at Three Months in the Gavage Study of Myristicin (H&E)

Figure 24

Hyaline Droplet Accumulation in the Respiratory Epithelium (Arrows) Along the Nasal Septum in a Level II Section of the Nose from a Male B6C3F1/N Mouse Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Brightly eosinophilic, homogeneous material expands the cytoplasm of respiratory epithelial cells. Compare to the normal respiratory epithelium in Figure 23.

Figure 25

Cytoplasmic Vacuolization in the Respiratory Epithelium (Arrows) Along the Nasal Septum in a Level II Section of the Nose from a Female B6C3F1/N Mouse Administered 600 mg/kg Myristicin by Gavage for Three Months (H&E)

Clear spaces expand the cytoplasm of respiratory epithelial cells. Compare to the normal respiratory epithelium in Figure 23.