# Materials and Methods

## Procurement and Characterization

### Myristicin

Myristicin was obtained from International Specialty Chemicals, Inc. (Tarrytown, NY), in one lot (PP/MYR/03-11-01) that was used in the 3-month studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle Chemistry Support Services (Columbus, OH) for the study laboratory at Battelle Columbus Operations (Columbus, OH) (Appendix F). Reports on the analyses performed in support of the myristicin studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a brownish orange to red, slightly sticky liquid was identified as myristicin using infrared and proton and carbon-13 nuclear magnetic resonance spectroscopy. The moisture content of lot PP/MYR/03-11-01 was determined by Galbraith Laboratories, Inc. (Knoxville, TN), using Karl Fischer titration. Elemental analyses of the bulk chemical for carbon and hydrogen were conducted by Prevalere Life Sciences, Inc. (Whitesboro, NY). The analytical chemistry laboratory determined the peroxide levels by titration and the purity of the test chemical using gas chromatography (GC) with flame ionization detection (FID) and high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection. Reportable impurities were further characterized by the analytical chemistry laboratory using GC and HPLC with mass spectrometry (MS) detection.

Karl Fischer titration indicated ≤0.16% water. Elemental analyses for carbon were in agreement with the theoretical values, but hydrogen values were slightly low; titration indicated the presence of no peroxide. GC/FID by one system indicated one major peak with 96.5% of the total peak area and four reportable impurities with a combined area of 3.5% of the total peak area and individual relative areas of 0.2%, 0.4%, 1.2%, and 1.7%. GC/MS identified two of the four impurities as tributylamine and eugenol; standard addition using GC/FID by a second system estimated their concentrations to be 0.31% and 1.25%, respectively. HPLC/UV analysis indicated one major peak with 94.1% of the total peak area and three reportable impurities with individual relative areas of 1.5%, 1.9%, and 2.5%. HPLC/MS identified two of the three impurities as 5-hydroxy-eugenol (1.9%) and eugenol (1.5%). Standard addition using HPLC/UV estimated the concentration of eugenol to be 1.1%. The purity of lot PP/MYR/03-11-01 was estimated to be greater than 94%.

Stability studies of the bulk chemical were performed using GC/FID. These studies indicated that myristicin was stable as a bulk chemical for at least 14 days when stored in sealed amber glass bottles at temperatures up to 25°C. To ensure stability, the bulk chemical was stored at approximately 5°C, protected from light, in sealed glass bottles. Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 3-month studies with GC/FID, and no degradation of the bulk chemical was detected.

### Corn Oil

Corn oil was obtained in two lots (098K0008 and 128K0040) from Sigma-Aldrich (St. Louis, MO) and was used as the vehicle in the 3-month studies. Periodic analyses of the corn oil performed by the study laboratory using potentiometric titration demonstrated peroxide concentrations less than the rejection level of 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared four times by mixing myristicin with corn oil to give the required concentrations. The dose formulations were stored at approximately 25°C in amber glass bottles sealed with Teflon^®^-lined lids for no longer than 42 days.

The analytical chemistry laboratory performed a gavagability study of a 200 mg/mL formulation and stability studies of the 1 mg/mL dose formulation using GC/FID. Gavagability was confirmed for a 22 gauge or larger needle. Stability was confirmed for at least 42 days for dose formulations stored in amber glass bottles sealed with Teflon^®^-lined lids at ambient and refrigerated temperatures and for at least 3 hours under simulated animal room conditions.

During the 3-month studies, the dose formulations of myristicin were analyzed three times by the study laboratory using GC/FID; all 27 dose formulations were within 10% of the target concentrations (Table F-3). Animal room samples of these dose formulations were also analyzed; 14 of 15 for rats and 14 of 15 for mice were within 10% of the target concentrations.

## Animal Source

Male and female F344/NTac rats were obtained from the commercial colony at Taconic BioSciences (formerly Taconic Farms, Inc.), Germantown, NY, and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic BioSciences. The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years, NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N rat exhibited sporadic seizures and idiopathic chylothorax, and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP to evaluate different rat models. The F344/NTac rat was used in four subchronic and two chronic studies between 2005 and 2006.^69^

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the AAALAC International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

On receipt, rats were 3 to 5 weeks old and mice were 4 to 5 weeks old. Animals were quarantined for 12 days; rats were 5 to 7 weeks old and mice were 6 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix H). All test results were negative.

Groups of 10 male and 10 female core study rats and mice were administered myristicin in corn oil by gavage at doses of 0, 10, 30, 100, 300, or 600 mg/kg body weight 5 days per week for 13 weeks. Additional groups of 10 male and 10 female clinical pathology study rats were administered the same doses for 21 days. Vehicle control animals received the corn oil vehicle alone. Dosing volumes were 5 mL/kg for rats and 10 mL/kg for mice. Feed and water were available ad libitum. Rats and female mice were housed five per cage, and male mice were housed individually. Animals were observed twice daily. The animals were weighed on day 1, weekly thereafter, and at the end of the studies; clinical observations were recorded postdosing on day 1, weekly thereafter, and at the end of the studies for core study rats and mice. Details of the study design and animal maintenance are summarized in Table 1. Information on feed composition and contaminants is provided in Appendix G.

Table 1 Experimental Design and Materials and Methods in the Three-month Gavage Studies of Myristicin

Three-month Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
F344/NTac rats B6C3F1/N mice
Animal Source
Taconic BioSciences (Germantown, NY)
Time Held Before Studies
Rats: 12 (males) or 13 (females) days Mice: 15 (males) or 14 (females) days
Average Age When Studies Began
Rats: 5 to 7 weeks Mice: 6 to 7 weeks
Date of First Dose
Rats: January 20 (males) or 21 (females), 2009 Mice: January 23 (males) or 22 (females), 2009
Duration of Dosing
5 days per week for 21 days (clinical pathology rats) or 13 weeks (core study rats and mice)
Date of Last Dose
Clinical pathology study rats: February 9 (males) or 10 (females), 2009 Core study rats: April 20 (males) or 21 (females), 2009 Mice: April 23 (males) or 22 (females), 2009
Necropsy Dates
Rats: April 21 (males) or 22 (females), 2009 Mice: April 24 (males) or 23 (females), 2009
Average Age at Necropsy
Rats: 18 to 20 weeks Mice: 19 to 20 weeks
Size of Study Groups
10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
Rats: 5
Mice: 1 (males) or 5 (females)
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least once weekly
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly (male mice) or twice weekly (rats and female mice)
Bedding
Irradiated Sani Chips® (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly (male mice) or twice weekly (rats and female mice)
Rack Filters
Spun-bonded polyester (Snow Filtration Co., Cincinnati, OH) changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Doses
0, 10, 30, 100, 300, or 600 mg/kg in corn oil; dosing volumes of 5 mL/kg (rats) or 10 mL/kg (mice)
Type and Frequency of Observation
Observed twice daily; animals were weighed on day 1, weekly thereafter, and at the end of the studies; clinical observations were recorded postdosing on day 1, weekly thereafter, and at the end of the studies for core study rats and mice.
Method of Euthanasia
100% Carbon dioxide
Necropsy
Necropsies were performed on all core study rats and mice. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
Blood was collected from the retroorbital plexus of clinical pathology study rats on days 3 and 22 and of core study rats at the end of the study for hematology and clinical chemistry. Blood was collected from the retroorbital sinus of mice at the end of the study for hematology. Hematology: hematocrit (automated and manual); hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, cholesterol, triglycerides, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids
Histopathology
Complete histopathology was performed on 0 and 600 mg/kg core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung (with mainstem bronchus), lymph nodes (mandibular and mesenteric), mammary gland (except male mice), nose, ovary, pancreas, pancreatic islets (mice), parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus. In addition, the kidney (males only), liver, lung, stomach (glandular), and testis (with epididymis) of rats; and the liver, nose, stomach (forestomach and glandular), and testis (with epididymis) of mice were examined in all remaining dosed groups. The salivary gland of male and female rats was examined to a no-observed-effect level.
Sperm Motility and Vaginal Cytology
At the end of the studies, spermatid and sperm samples were collected from male animals in the 0, 100, 300, and 600 mg/kg groups. The following parameters were evaluated: spermatid heads per gram testis and per testis, sperm motility, and sperm per gram cauda epididymis and per cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for 16 consecutive days prior to the end of the studies from females in the 0, 100, 300, and 600 mg/kg groups for vaginal cytology evaluations.

Animals were anesthetized with a carbon dioxide and oxygen mixture (CO_2_:O_2_ mixture at 70%:30%) and blood was collected from the retroorbital plexus of clinical pathology study rats on days 3 and 22 and from core study rats at study termination for hematology and clinical chemistry; blood was collected from the retroorbital sinus of mice for hematology analyses at study termination. The blood samples were collected into tubes containing EDTA for hematology determinations or serum separator tubes for clinical chemistry (Table 1). The following hematology parameters were determined using an Advia^®^ 120 Hematology Analyzer (Bayer Diagnostics Division, Tarrytown, NY): hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials. A manual hematocrit was also performed. Peripheral blood smears were evaluated for any morphological abnormalities. Serum was analyzed for the following clinical chemistry parameters using a Cobas^®^ c 501 chemistry analyzer (Roche Diagnostics Corporation, Indianapolis, IN): urea nitrogen, creatinine, glucose, total protein, albumin, cholesterol, triglyceride and bile acid concentrations, and alanine aminotransferase, alkaline phosphatase, creatine kinase, and sorbitol dehydrogenase activities.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats and mice in the 0, 100, 300, and 600 mg/kg groups. The parameters evaluated are listed in Table 1. For 16 consecutive days prior to scheduled terminal euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained; however, due to technical issues with sample collection, an assessment of estrous cyclicity could not be made. Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrone’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin; however, the eyes were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides were first fixed in modified Davidson’s solution. All tissues were trimmed, processed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Additional sections of the kidney from male rats were stained with the Mallory-Heidenhain stain for detection of protein. The study pathologist performed complete histopathologic examinations on rats and mice from the vehicle control and 600 mg/kg groups. The liver, glandular stomach, kidney (males only), testis, epididymis, and lung of rats; and the liver, stomach, testis, epididymis, and nose of mice were examined in all remaining dosed groups. The salivary gland of male and female rats was examined to a no-observed-effect level (300 mg/kg for males and 100 mg/kg for females). Table 1 lists the tissues and organs routinely examined.

Evaluation of the rat sperm parameters suggested an effect on spermatogenesis, but there was no microscopic correlation found during the routine pathology examination of the tissues from the 3-month studies. Therefore, a detailed qualitative histopathologic examination was conducted on H&E-stained slides of testes and epididymides from the rats and mice. Tubular stages of the spermatogenic cycle were taken into account in order to identify potential findings.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to an NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. A special pathology peer review was convened following the initial PWG to evaluate the testes and epididymides. Details of these review procedures have been described, in part, by Maronpot and Boorman^70^ and Boorman et al.^71^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^72^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^73^ and Williams.^74,75^ Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^76^ (as modified by Williams^77^) and Dunn.^78^ Jonckheere’s test^79^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^80^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^81^ In addition, as records from the 3-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicology

### Salmonella typhimurium Mutagenicity Test Protocol

Testing procedures were those reported by Zeiger et al.^82^ Briefly, a commercially obtained sample of myristicin was sent to the laboratory under code. It was incubated with each of the Salmonella typhimurium tester strains (TA97, TA98, TA100, and TA1535) either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C. Each trial consisted of triplicate plates of concurrent positive and negative controls and at least five doses of myristicin. The high dose was limited by toxicity. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Rat and Mouse Peripheral Blood Micronucleus Test Protocol

At the termination of the 3-month studies, blood samples were collected from male and female rats and mice, placed in EDTA-coated tubes, fixed in ultracold methanol, and frozen at −80°C until analysis. Thawed blood samples were analyzed for frequency of micronucleated reticulocytes (polychromatic erythrocytes, PCEs) and mature erythrocytes (normochromatic erythrocytes, NCEs) using a flow cytometer^83^; both the mature erythrocyte population and the immature reticulocyte population can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte population can be targeted using this technique, rat blood samples can be analyzed for damage in the bone marrow that occurred within the past 24 to 48 hours, before the rat spleen appreciably alters the percentage of micronucleated reticulocytes in circulation.^84^ In mice, both the reticulocyte and mature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. These achieve steady state in the peripheral blood of mice following 4 weeks of continuous exposure. Approximately 20,000 PCEs and 1 × 10^6^ NCEs are analyzed per sample for frequency of micronucleated cells, and the percent PCEs is calculated as a measure of bone marrow toxicity resulting from chemical exposure.

Based on prior experience with the large number of cells scored using flow cytometric scoring techniques,^85,86^ it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose and Williams’ test is used to test for pairwise differences between each treatment group and the control group. In the case of unequal variances, Jonckheere’s test is used to test for linear trend and Dunn’s test is used for pairwise comparisons of each treatment group with the control group. Trend tests and pairwise comparisons with the controls are considered statistically significant for PCEs and NCEs when the one-sided P-value is less than 0.025, and for percent PCEs when the two-sided P-value is less than 0.05. In the micronucleus test, for each of the endpoints evaluated, a positive result is preferably based on the presence of both a significant trend as well as at least one significantly elevated dose group compared with the corresponding control group. The presence of either a significant trend or a single significant dose group generally results in an equivocal call. The absence of both a trend and a significant dose group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this Toxicity Study Report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.