# Introduction

Figure 1

Myristicin (CASRN 607-91-0; Chemical Formula: C_11_H_12_O_3_; Molecular Weight: 192.21)

Synonyms: 1-Allyl-5-methoxy-2,3-methylenedioxybenzene; 5-allyl-1-methoxy-2,3,-(methylenedioxy)benzene; 1-methoxy-2,3-methylenedioxy-5-allyl benzene; 4-methoxy-6-prop-2-enyl-1,3-benzodioxole.

## Chemical and Physical Properties

The naturally occurring alkenylbenzene, myristicin, is a volatile, fragrant, and colorless oil. Myristicin has a specific gravity of 1.1416 g/mL at 20ºC, a melting point lower than −20ºC, a boiling point of 276.5ºC, and a vapor pressure of 0.00646 mmHg at 25ºC. Myristicin is soluble in benzene and ether, slightly soluble in ethanol, and insoluble in water.^1^ As a member of the alkoxy-substituted allylbenzene family, myristicin shares many physical and chemical properties with the food additives apiole, safrole, elemicin, estragole, and methyleugenol.^2^

## Production, Use, and Human Exposure

Exposure to myristicin is largely limited to ingestion of certain spices or plants and products incorporating their essential oils and oleoresins. Principally, myristicin is derived from the tropical evergreen tree Myristica fragrans Houtt. (Myristicaceae). Myristicin is a major constituent in essential oil extracted from either the seed (0.25% to 3.28%), which is the source of the spice nutmeg, or the aril covering the seed (0.25% to 5.92%), which is the source of the spice mace, of M. fragrans.^3-7^ Myristicin is also in the oleoresin fraction of nutmeg and mace; one study reported 4.5% and another reported 8.1% myristicin in nutmeg oleoresin.^7,8^ Other notable components of nutmeg oil include elemicin, safrole, eugenol, isoeugenol, and methyleugenol.^9-11^ Besides M. fragrans, the chemical myristicin is present in some plants of the Apiaceae family, including dill and parsley, as well as in celery, carrot, and parsnip.^4,10,12^ Essential oils derived from these natural sources of myristicin are an important consideration when estimating myristicin exposure, the largest sources being nutmeg and mace.^2^ The percentage of myristicin in dill herb aromatic fraction is 2.81% to 7.63% and in essential oil from parsley leaf, myristicin is as low as 1% and as high as 60%.^13,14^

Nutmeg and mace are used widely as spices in a variety of cuisines. Essential oil extracted from nutmeg is used as a flavoring in various products, including soft drinks and cigarettes, sauces, baked goods, processed foods, and condiments, and as a fragrance in perfumes and cosmetics.^15-18^ Exposure to myristicin is largely via ingestion, although inhalation and dermal exposure may be secondary routes, especially for those involved in the farming, transport, or processing of nutmeg. Import of nutmeg to the United States was nearly 4.5 million pounds each year in 2011, 2012, and 2013; an increase from 4 million pounds in 1971.^15,19^ Percentages of myristicin in nutmeg and mace, and their essential oils, vary considerably depending upon the source and the processing technique.^20^ Archer^21^ found that myristicin comprises 1.14% to 2.54% of powdered nutmeg and 2.59% to 7.55% of powdered mace. Pure myristicin may be isolated from natural products, synthesized from pine oil, or derived synthetically from eugenol for research purposes.^22,23^ Absolute exposure of an individual to myristicin is difficult to estimate, due to the varying levels in essential oils and the large variation in spices and essential oils consumed. Based on the amount of essential oil from nutmeg and mace used in the United States food supply annually, the Food and Drug Administration^15^ proposed an estimated exposure of 0.05 mg essential oil/kilogram body weight per day for adults. Based on intake of myristicin from the most frequent sources, such as condiments, nonalcoholic beverages, frozen dairy, processed vegetables, and baked goods, one study estimated average total intake of myristicin to be a few mg per person per day.^4^ More recently, assuming the highest concentration of myristicin in essential oils, from nutmeg and other sources, the World Health Organization estimated intake of myristicin to be less than 1 mg/day.^2^

## Regulatory Status

There are currently no FDA regulations regarding the levels of powders, oil, or oleoresins from nutmeg, mace, parsley, or dill or pure myristicin allowable in pharmaceutical or food products. Nutmeg, mace, dill, parsley, and the essential oils derived from these spices have been generally recognized as safe.^15,24,25^ Similarly, there are no guidelines set forth by the Occupational Safety and Health Administration of acceptable levels in industrial settings. There are no guidelines or laws regarding the production or sale of synthetic myristicin or myristicin isolated from natural sources.

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

### Experimental Animals

There have been no comprehensive toxicokinetic (TK) studies or absorption, distribution, metabolism, and excretion (ADME) studies completed on myristicin to date; however, a few studies have reported in vitro and in vivo metabolism of myristicin in various species. Overall, these studies suggest that the myristicin was well absorbed following oral exposure, metabolized extensively, and excreted as CO_2_ and in the urine of experimental animals.^26-29^

Male Swiss-Webster mice administered 5 µmol/kg radiolabeled myristicin by stomach tube were found to expire up to 73% as CO_2_ after 48 hours, potentially formed from the hydroxylation of the methylene group of myristicin.^26,27^ Of the remaining radioactivity, 15% was recovered in urine, 3% in feces, 3% in intestine, and 1.5% in liver.

Myristicin was found to have several routes of metabolism, including hydroxylation, demethylenation, and methylation. In male Wistar rats administered myristicin (100 mg/kg) once by oral gavage,^29^ the metabolites identified in urine included 1-hydroxy-1-(3′,4′-methylenedioxy-5′-methoxyphenyl)-prop-2-ene, 1-(3′,4′-dihydroxy-5′-methoxyphenyl)-prop-2-ene, 1-(3′,5′-dimethoxy-4′-hydroxyphenyl)-prop-2-ene, 1-(3′,4′-methylenedioxy-5′-hydroxyphenyl)-prop-2-ene, and 2,3-dihydroxy-1-(3′,4′-methylenedioxy-5′-methoxy phenyl)-propane (Figure 2). Isolation of these metabolites in Sprague Dawley rat urine after a single oral administration of myristicin (100 mg/kg), and comparison before and after glucuronidase treatment, suggests that these metabolites are also excreted in their respective conjugated forms.^28^ Oswald et al.^30^ found that intraperitoneal injection of myristicin in rats and guinea pigs yielded 3-piperidyl-1-(3′-methoxy-4′,5′-methylenedioxyphenyl)-1-propanone and 3-pyrrolidinyl-1-(3′-methoxy-4′,5′-methylenedioxyphenyl)-1-propanone as the respective major urinary metabolites. This suggests that the many pathways of myristicin metabolism vary in prevalence depending upon species and route of exposure, and may indeed include amination of the allyl group.

Figure 2

Urinary Metabolites of Myristicin in Rats

Myristicin has the capacity to induce enzymes involved in xenobiotic metabolism. Male Sprague Dawley rats administered myristicin (10 to 500 µmol/kg) intraperitoneally exhibited a dose-dependent increase in microsomal cytochrome P450 (CYP) activity, including CYP1A1/1A2, CYP2B1/2B2, and CYP2E1.^31^ In mouse cells, myristicin was found to induce CYP1A1.^32^ Myristicin has also been shown to induce glutathione-S-transferase (GST) activity. Female A/J mice orally administered 30 mg myristicin over the course of 6 days exhibited increased levels of hepatic and intestinal GST activity.^33^ A similar GST activity induction was observed in albino mice, which exhibited a preferential induction of GSTµ expression over GSTπ and GSTα.^34^

Incubation of myristicin in rat liver microsomes formed two major metabolites, 1′-hydroxymyristicin and 5-allyl-1-methoxy-2,3-dihydroxy-benzene,^28^ which are the same metabolites identified in the Beyer et al.^29^ study, 1-(3′,4′-dihydroxy-5′-methoxyphenyl)-prop-2-ene and 1-hydroxy-1-(3′,4′-methylenedioxy-5′-methoxyphenyl)-prop-2-ene. One study, using isolated perfused rat liver, found that the liver is also capable of biotransforming myristicin into 3-methoxy-4,5-methylenedioxyamphetamine, and proposed it as the likely mechanism for psychoactive activity of myristicin in instances of nutmeg overdose.^35^ No other studies have identified amphetamine derivatives of myristicin, or any other safrole-related compound studied.

### Humans

There have been no comprehensive studies in humans. However, one study examined metabolites present in the urine of a patient who had ingested five nutmeg seeds resulting in an overdose.^29^ Of the metabolites detected, 2,3-dihydroxy-1-(3′,4′-methylenedioxy-5′-methoxyphenyl)-propane may have been derived from myristicin, 1-(3′,5′-dimethoxy-4′-hydroxyphenyl)-prop-2-ene may have been derived from myristicin or estragole, and 1-(3′,4′-methylenedioxy-5′-hydroxyphenyl)-prop-2-ene and 1-(3′,4′-dihydroxy-5′-methoxyphenyl)-prop-2-ene may have been formed from several nutmeg components. Biotransformation of myristicin in human liver microsomes to one of its major metabolites, 5-allyl-1-methoxy-2,3-dihydroxy-benzene, was found to be catalyzed by CYP3A4 and, to a lesser extent, CYP1A2.^36^

## Toxicity

Because exposure to myristicin is limited to ingestion of plants and spices of which myristicin is one of many components, it is difficult to delineate the toxicologic responses specific to myristicin. Although myristicin is believed to be the active component of nutmeg oil, there is still some ambiguity as to whether its relative potency can fully explain nutmeg intoxication. Therefore, the reports summarized herein include studies on both nutmeg and myristicin.

### Experimental Animals

Perhaps due to the long history of nutmeg as a traditional home remedy, there have been several studies on the therapeutic and toxicologic properties both of nutmeg and of pure myristicin. Investigation into the hypolipidemic effect of nutmeg extract in rabbits revealed the ability to lower levels of total cholesterol in heart and liver (500 mg/kg over 60 days) with no toxicologically significant clinical effects.^37^ In benzo[α]pyrene-induced tumor female A/J mouse model, myristicin exposure was associated with a 65% reduction in lung tumor formation and a 31% reduction in forestomach tumor formation after 18 weeks.^33^ Myristicin was also shown to be hepatoprotective, attenuating the increased serum ALT and AST activities and DNA fragmentation in mouse livers following administration of lipopolysaccharide and D-galactosamine.^38^ Myristicin has been found to have antibacterial, antifungal, and insecticidal activity, as well as to enhance the effectiveness of other insecticides.^12,39,40^

There are few studies reported that investigate the toxicity of nutmeg or myristicin in experimental animals. In a 42-day study in adult Wistar rats, oral administration of nutmeg spice (500 and 1,000 mg/kg) displayed degeneration and atrophy of the kidney.^41^ However, in another study, male white rats (strain not specified) administered 10 mg/kg myristicin per day for 26 days exhibited no changes in body weight and no abnormalities of the liver or kidney.^42^

Acute administration of nutmeg essential oil (0.5 mL/cage) to mice by inhalation resulted in inhibition of locomotion, and disruption of rope-climbing and bar-pressing activities.^11,43^ Rats and guinea pigs dosed with myristicin (5 to 20 mg/kg intraperitoneal injection) were hyperactive for the first 30 minutes after exposure and then become sedated and nonresponsive for up to 2 hours.^30^ Myristicin may promote anxiolytic behavior in male Sprague Dawley rats dosed with midazolam.^44^ A mouse tetrad study, characterizing the effect of nutmeg extract on locomotor activity, catalepsy, body temperature, and nociception compared to cannabinoids and amphetamines revealed that nutmeg-related responses depended upon the extraction method and route of exposure.^45^ Oral administration of nutmeg extracts exhibited a stimulating effect on locomotor activity similar to amphetamine; whereas intraperitoneal administration of extracts led to either no effect or a depressive effect on locomotor activity and hypothermia similar to what is seen with cannabinoids.

### Humans

Nutmeg has been used for centuries in traditional home remedies to treat illnesses ranging from rheumatism to various intestinal ailments including dysentery and cholera, kidney disorders, gastrointestinal disorders including distended stomach, diarrhea, and flatulence, or as a remedy for overeating, whooping cough, and for healing after childbirth.^5,10,46^ As a home remedy, nutmeg was used as a sedative, and nutmeg butter was often used in soap due to its purported ability to reinvigorate the skin and heal boils.^46^ Nutmeg was also believed to cure madness and relieve headaches, and it was speculated to be an abortifacient at high doses.^10,46^

Toxic outcomes related to myristicin in humans are largely associated with acute overdoses of nutmeg, the symptoms of which are generally attributed to myristicin. Ingestion of excessive amounts of nutmeg (as little as one and a half seeds and up to 19 seeds) can result in a delirious stupor, with a combination of stimulation and drowsiness or weakness similar to opium and other narcotics.^10,47,48^ Patients with nutmeg overdose present with facial flushing, tachycardia, hypertension, blurred vision, dry mouth, psychoactive hallucinations, and feelings of euphoria, anxiety, and fear; symptoms typically subside after 24 to 36 hours.^5,49^ Intoxication can be accidental, occurring when individuals would ingest too much nutmeg as a home remedy.^10^

In the modern era, overdoses are more likely to occur due to intentional ingestion of nutmeg as an inexpensive and legal alternative or addition to other abuse substances.^50^ There have been several case reports of nutmeg overdoses in recent decades. A German poison information center in Erfurt reported seven cases of nutmeg poisoning from 1996 to 1998, ranging from suspended nutmeg powder (14 to 80 grams) to full nutmeg seeds (up to 19).^48^ A retrospective review in an Illinois poison center revealed that, from 2001 to 2011, 32 cases of nutmeg ingestion were reported. Approximately 47% were intentional, and almost all the intentional exposures occurred in teenagers, often as a coexposure with drugs of abuse.^50^ A similar retrospective review in California, from 1997 to 1998, reported 119 single-substance exposures to nutmeg, with 72% of them reported as intentional.^51^ Nevertheless, to date, only two nutmeg-related deaths have been reported: one 8-year-old boy who ingested two nutmeg seeds (estimated 560 to 840 mg/kg of nutmeg) and one woman whose death was attributed to a drug-drug interaction between myristicin and flunitrazepam.^48,52^

In the occupational exposure realm, a sampling of spice workers suggests that the processing of nutmeg does not generally elicit allergic responses, although one report of occupational asthma due to exposure to mace, which contains myristicin, has been recorded.^53,54^ Among patients tested for contact allergy to spices, 28% of the 32 patients who tested positive were allergic to nutmeg.^55^ There is no information about whether these responses are due to myristicin, or other components of nutmeg.

## Reproductive and Developmental Toxicity

### Experimental Animals

In a report prepared for the FDA that evaluated the health aspects of nutmeg, mace, and their essential oils as food ingredients, results of available prenatal developmental toxicity studies were summarized. Oil of nutmeg was administered to CD-1 mice (up to 560 mg/kg), Wistar rats (up to 260 mg/kg), and hamsters (up to 600 mg/kg) through species-specific gestation periods (GD 6-15 for rats and mice, GD 6-10 for hamsters). No discernible changes in maternal or fetal survival, nor any malformations of the soft or skeletal tissues were observed in the experimental groups.^56^ No studies directly addressing reproductive or developmental toxicity of myristicin in experimental animals have been published; however, there is some evidence of transplacental transfer of myristicin. One study identified alkenylbenzene-DNA adducts in fetal mouse liver after maternal exposure to myristicin by gastric intubation.^16^

### Humans

There are no studies on the reproductive or developmental effects of either nutmeg or myristicin in humans. Although nutmeg was historically rumored to have abortifacient properties, these claims have not been substantiated in the recent scientific literature.^5^

## Carcinogenicity

### Experimental Animals

To date, there have been no 2-year exposure studies on myristicin to investigate carcinogenicity. Safrole, a structurally related chemical, is hepatocarcinogenic in mouse and rat and is reasonably anticipated to be a human carcinogen.^57^ Methyleugenol was found by the National Toxicology Program (NTP) to be a hepatocarcinogen in male and female rats and is reasonably anticipated to be a human carcinogen.^58,59^ A panel of predictive models developed using alkenylbenzene toxicology data from subchronic studies suggested that when compared against known hepatocarcinogenic alkenylbenzenes, myristicin would likely be a weak carcinogen if studied at a dose level of 2 mmol/kg body weight per day for 2 years in male F344 rats.^60^ Another study canvassed 23 alkenylbenzene derivatives for hepatocarcinogenic potential in mice. Myristicin was repeatedly administered to CD-1 mice over the first 22 days after birth (4.75 µmol).^61^ After 13 and 18 months, myristicin-exposed animals exhibited a greater number of hepatomas, but the difference did not reach statistical significance compared to controls that received no treatment.

### Humans

There are no studies investigating whether exposure to myristicin is associated with increased cancer incidence in humans.

## Genetic Toxicity

Myristicin is metabolized to an electrophilic compound that forms DNA adducts. The 1ʹ-carbon of the allyl side chain of alkenylbenzenes undergoes Phase I hydroxylation.^28^ The resultant 1ʹ-hydroxyl group is a target for Phase II conjugation by sulfotransferase; however, the O-sulfation product is unstable and a carbonium ion is generated when the sulfate group leaves.^62^ This carbonium ion forms a major and a minor DNA adduct at the N^2^ position of guanine residues.^63,64^

The formation of myristicin-DNA adducts in the livers of mice has been demonstrated in male B6C3F1 mice and female CD-1 mice exposed via intraperitoneal injection, female ICR mice exposed via oral gavage, and pregnant ICR mice and their fetuses when the dams were exposed via oral gavage.^16,63,65^ Myristicin-DNA adducts were also detected in vitro in a human hepatoma (HepG2) cell line that exhibits metabolic activity.^64^

Although myristicin forms DNA adducts in mice in vivo and human cells in vitro, exposure to myristicin did not result in phosphorylation of H2AX, a marker of double-strand DNA breaks, in Chinese hamster ovary (CHO) cells, nor did it increase DNA migration, indicative of DNA damage, in CHO cells as measured in the comet assay when tested up to a concentration that reduced cell viability by 50%.^66^ Deficiency for the DNA nucleotide excision repair protein, ERCC1, did not affect these results or increase the cytotoxic effects of myristicin.^66^ However, an exogenous metabolic activation system was not used in these CHO cell experiments. In freshly-isolated hepatocytes from male Fischer 344 rats, in vitro exposure to myristicin produced a dose-dependent but modest level of unscheduled DNA synthesis, an indicator of DNA excision repair activity.^67^

DNA adduct formation and DNA damage were assessed using an avian egg model.^68^ Turkey eggs were injected with myristicin once a day on days 22 through 24 of incubation and embryos were removed 3 hours after the last injection. Adduct levels and DNA damage were assessed in each developing liver. Myristicin-DNA adducts were formed in turkey embryos, and small but statistically significant increases in DNA damage were observed using the comet assay.

## Study Rationale and Design

Myristicin was first nominated by the National Cancer Institute for metabolism, genetic toxicology, and carcinogenicity studies due to high potential for human exposure from natural sources and use as a flavoring in food substances. Additionally, myristicin bears structural similarity to safrole, estragole, and other members of the alkenylbenzene family. Based on these similarities, the current studies were conducted to better characterize the toxicity of myristicin in F344/NTac rats and B6C3F1/N mice over 3 months of exposure. To facilitate comparison with NTP studies of other alkenylbenzene flavorings, gavage was chosen as the route of exposure, and comparable doses were selected.