# Appendix F Chemical Characterization and Dose Formulation Studies

## F.1 Procurement and Characterization of Myristicin

Myristicin was obtained from International Specialty Chemicals, Inc. (Tarrytown, NY), in one lot (PP/MYR/03-11-01) that was used in the 3-month studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle Chemistry Support Services (Columbus, OH) for the study laboratory at Battelle Columbus Operations (Columbus, OH). Reports on the analyses performed in support of the myristicin studies are on file at the National Institute of Environmental Health Sciences.

Lot PP/MYR/03-11-01 of the chemical, a brownish orange to red, slightly sticky liquid was identified as myristicin using infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy. IR spectra were consistent with absorption assignments expected for myristicin; proton and carbon-13 nmR spectra were consistent with chemical shifts predicted for myristicin by an Advanced Chemistry Development, Inc. (ACD/Labs, Toronto, Ontario, Canada), spectral prediction program. Representative IR and proton and carbon-13 nmR spectra are presented in Figure F-1, Figure F-2, and Figure F-3, respectively.

The moisture content of lot PP/MYR/03-11-01 was determined by Galbraith Laboratories, Inc. (Knoxville, TN), using Karl Fischer titration. Elemental analyses of the bulk chemical for carbon and hydrogen were conducted by Prevalere Life Sciences, Inc. (Whitesboro, NY). The analytical chemistry laboratory determined the peroxide levels by titration and the purity of the test chemical using gas chromatography (GC) with flame ionization detection (FID), and high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection. Reportable impurities were further characterized by the analytical chemistry laboratory using GC and HPLC with mass spectrometry (MS) detection. Peroxide content was determined using sodium thiosulfate titration of a solution of myristicin and potassium iodide. HPLC/UV analysis of the purity of the sample was determined using system I.

I) The system included an HPLC instrument (Agilent, Palo Alto, CA), a Luna C18, 150 mm × 4.6 mm, 5 µm particle size column (Phenomenex, Torrance, CA), mobile phases of A) 50:50:1 acetonitrile:water:acetic acid and B) 90:10:1 acetonitrile:water:acetic acid, a linear gradient of 100% A for 20 minutes to 100% B in 5 minutes, held for 20 minutes, then to 100% A in 5 minutes, held for 15 minutes, UV detection at 230 nm, and a flow rate of 0.7 mL/minute.

Karl Fischer titration indicated ≤0.16% water. Elemental analyses for carbon (68.31%) were in agreement with the theoretical values (99.4% of theoretical), but hydrogen values were slightly low (85.9% of theoretical); titration indicated the presence of no peroxide. GC/FID using system A (Table F-1) indicated one major peak with 96.5% of the total peak area and four reportable impurities with individual relative areas of 0.2%, 0.4%, 1.2%, and 1.7%. GC/MS using system B identified two of the four impurities as tributylamine and eugenol; standard addition using GC/FID by system C estimated their concentrations to be 0.31% and 1.25%, respectively. HPLC/UV using system I indicated one major peak with 94.1% of the total peak area and three reportable impurities with individual relative areas of 1.5%, 1.9%, and 2.5%. HPLC/MS conducted with a Quattro LC mass spectrometer (Waters-Micromass, Manchester, England) for detection and a system otherwise similar to system I identified two of the three impurities as 5-hydroxy-eugenol (1.9%) and eugenol (1.5%). An additional HPLC/MS analysis using this system except for reduction of the acetic acid fractions of mobile phases A and B from 1% to 0.1% and reduction of the final gradient hold to 5 minutes tentatively identified the third impurity as an isomer of 4-allyl-2-methoxyphenyl acetate or a structurally similar compound with a molecular weight of 206. Standard addition using HPLC/UV by system I estimated the concentration of eugenol to be 1.1%. The overall purity of lot PP/MYR/03-11-01 was estimated to be greater than 94%.

Stability studies of the bulk chemical were performed using GC/FID by system C. These studies indicated that myristicin was stable as a bulk chemical for at least 14 days when stored in sealed amber glass bottles at temperatures up to 25°C. To ensure stability, the bulk chemical was stored at approximately 5°C, protected from light, in sealed glass bottles. Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 3-month studies with GC/FID by system C. No degradation of the bulk chemical was detected.

### F.1.1 Corn Oil

Corn oil was obtained from Sigma-Aldrich (St. Louis, MO) in two lots (098K0008, 128K0040) and was used as the vehicle in the 3-month studies. Periodic analyses of the corn oil performed by the study laboratory using potentiometric titration demonstrated peroxide concentrations less than the rejection level of 3 mEq/kg.

## F.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared four times by mixing myristicin with corn oil to give the required concentrations (Table F-2). The dose formulations were stored at approximately 25°C in amber glass bottles sealed with Teflon^®^-lined lids for no longer than 42 days.

The analytical chemistry laboratory performed a gavagability study of a 200 mg/mL formulation and stability studies of the 1 mg/mL dose formulation using GC/FID by system C (Table F-1). Gavagability was confirmed for a 22 gauge or larger needle. Stability was confirmed for at least 42 days for dose formulations stored in amber glass bottles sealed with Teflon^®^-lined lids at ambient and refrigerated temperatures and for at least 3 hours under simulated animal room conditions.

Periodic analyses of the dose formulations of myristicin were conducted by the study laboratory using GC/FID by system C. During the 3-month studies, the dose formulations were analyzed three times; all 27 dose formulations were within 10% of the target concentrations (Table F-3). Animal room samples of these dose formulations were also analyzed; 14 of 15 for rats and 14 of 15 for mice were within 10% of the target concentrations.

Table F-1 Gas Chromatography Systems Used in the Three-month Gavage Studies of Myristicin^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | RTX^®^-5, 30 m × 0.53 mm, 1.0 µm film (Restek, Bellefonte, PA) | Helium at 5 mL/minute | 50°C for 3 minutes, then 10°C/minute to 300°C, held for 2 minutes
System B
Mass spectrometry with electron impact ionization (50 to 500 amu) | RTX^®^-5, 30 m × 0.32 mm, 1.0 µm film (Restek) | Helium at 5 mL/minute | 50°C for 3 minutes, then 10°C/minute to 300°C, held for 2 minutes
System C
Flame ionization | RTX^®^-5, 30 m × 0.32 mm, 1.0 µm film (Restek) | Helium at 5 mL/minute | 50°C for 1 minute (dose formulation analysis and stability studies) or 3 minutes (bulk chemical impurity quantification, periodic reanalysis, and stability studies), then 10°C/minute to 300°C, held for 2 minutes

^a^ The gas chromatographs and mass spectrometer were manufactured by Agilent Technologies, Inc. (Santa Clara, CA).

Table F-2 Preparation and Storage of Dose Formulations in the Three-month Gavage Studies of Myristicin

Three-month Studies
Preparation
Approximately 200, 700, or 900 mL of corn oil was placed into a calibrated glass mixing container and the appropriate amount of myristicin was added (with corn oil rinsing) to achieve approximately 90% of the final volume in the mixing container for the 1, 3, 10, and 30, 2, 6, 20, and 120, and 60 mg/mL dose formulations, respectively. Each mixing container was then diluted to final volume with corn oil, and the contents were stirred using a stir bar and stir plate or an overhead stirrer for approximately 10 minutes.
Chemical Lot Number
PP/MYR/03-11-01
Maximum Storage Time
42 days
Storage Conditions
Stored in sealed glass bottles protected from light at room temperature
Study Laboratory
Battelle Columbus Operations (Columbus, OH)

Table F-3 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Gavage Studies of Myristicin

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
January 6, 2009 | January 8, 2009 | 2 | 2.05 | +3
| | 6 | 6.17 | +3
| | 20 | 20.0 | 0
| | 60 | 59.6 | −1
| | 120 | 119 | −1
| February 24, 2009^b^ | 2 | 1.92 | −4
| | 6 | 5.76 | −4
| | 20 | 19.1 | −4
| | 60 | 56.4 | −6
| | 120 | 128 | +7
February 27, 2009 | March 3, 2009 | 2 | 1.94 | −3
| | 6 | 5.90 | −2
| | 20 | 19.9 | −1
| | 60 | 59.1 | −2
| | 120 | 117 | −3
| April 14, 2009^b^ | 2 | 2.06 | +3
| | 6 | 6.32 | +5
| | 20 | 17.8 | −11
| | 60 | 58.6 | −2
| | 120 | 118 | −2
April 1, 2009 | April 6, 2009 | 2 | 1.93 | −4
| | 6 | 5.85 | −3
| | 20 | 19.4 | −3
| | 60 | 56.6 | −6
| | 120 | 118 | −2
| April 24, 2009^b^ | 2 | 1.95 | −3
| | 6 | 5.96 | −1
| | 20 | 19.7 | −2
| | 60 | 58.2 | −3
| | 120 | 115 | −4
Mice
January 6, 2009 | January 8, 2009 | 1 | 0.997 | 0
| | 3 | 3.11 | +4
| | 10 | 9.99 | 0
| | 30 | 30.2 | +1
| | 60 | 59.6 | −1
| February 24, 2009^b^ | 1 | 0.966 | −3
| | 3 | 2.89 | −4
| | 10 | 9.71 | −3
| | 30 | 28.4 | −5
| | 60 | 56.1 | −7
February 27, 2009 | March 3, 2009 | 1 | 0.955 | −5
| | 3 | 2.84 | −5
| | 10 | 9.90 | −1
| | 30 | 29.8 | −1
| | 60 | 59.1 | −2
| April 14, 2009^b^ | 1 | 0.899 | −10
| | 3 | 2.74 | −9
| | 10 | 8.09 | −19
| | 30 | 29.3 | −2
| | 60 | 59.0 | −2
April 1, 2009 | April 6, 2009 | 1 | 0.916 | −8
| | 3 | 2.92 | −3
| | 10 | 9.53 | −5
| | 30 | 28.6 | −5
| | 60 | 56.6 | −6
| April 24, 2009^b^ | 1 | 0.930 | −7
| | 3 | 2.90 | −3
| | 10 | 9.65 | −4
| | 30 | 28.6 | −5
| | 60 | 56.1 | −7

^a^ Results of duplicate analyses. For rats, dosing volume = 5 mL/kg; 2 mg/mL = 10 mg/kg, 6 mg/mL = 30 mg/kg, 20 mg/mL = 100 mg/kg, 60 mg/mL = 300 mg/kg, 120 mg/mL = 600 mg/kg. For mice, dosing volume = 10 mL/kg; 1 mg/mL = 10 mg/kg, 3 mg/mL = 30 mg/kg, 10 mg/mL = 100 mg/kg, 30 mg/mL = 300 mg/kg, 60 mg/mL = 600 mg/kg.

^b^ Animal room samples.

Figure F-1

Infrared Absorption Spectrum of Myristicin

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of Myristicin

Figure F-3

Carbon-13 Nuclear Magnetic Resonance Spectrum of Myristicin