# Appendix E Genetic Toxicology

Table E-1 Mutagenicity of Myristicin in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% hamster S9 | With 30% hamster S9 | With 10% rat S9 | With 30% rat S9
TA100
| 0 | 112 ± 7 | 87 ± 2 | 118 ± 6 | 106 ± 9 | 89 ± 5 | 135 ± 5
| 3.3 | 108 ± 5 | 91 ± 19
| 10 | 109 ± 1 | 105 ± 19 | 130 ± 8 | 120 ± 6 | 86 ± 3 | 137 ± 10
| 33 | 111 ± 4 | 87 ± 13 | 130 ± 5 | 127 ± 8 | 92 ± 3 | 132 ± 5
| 100 | 81 ± 14^b^ | 72 ± 3 | 128 ± 7 | 91 ± 2 | 97 ± 4 | 129 ± 16
| 217 | Toxic | Toxic
| 333 | | | 92 ± 8^b^ | 120 ± 7 | 54 ± 2^b^ | 125 ± 8
| 833 | | | 87 ± 10^b^ | 51 ± 23^b^ | Toxic | 30 ± 29^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control^c^ | | 517 ± 48 | 410 ± 8 | 251 ± 21 | 465 ± 4 | 427 ± 20 | 562 ± 131
TA97
| 0 | 153 ± 8 | 176 ± 10 | 136 ± 7 | 211 ± 3
| 3.3 | 155 ± 10 | 171 ± 8
| 10 | 150 ± 9 | 136 ± 8 | 182 ± 8 | 242 ± 12
| 33 | 154 ± 1 | 148 ± 11 | 127 ± 6 | 250 ± 7
| 100 | 88 ± 4^b^ | 132 ± 12 | 176 ± 21 | 202 ± 23
| 217 | Toxic | Toxic
| 333 | | | 75 ± 7^b^ | 152 ± 8^b^
| 833 | | | 4 ± 0^b^ | 0 ± 0^b^
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 463 ± 7 | 377 ± 32 | 455 ± 24 | 992 ± 28
| | With 10% rat S9 | With 10% rat S9 | With 30% rat S9
TA97 (continued)
| 0 | 130 ± 10 | 148 ± 8 | 222 ± 8
| 1 | | 143 ± 4
| 3.3 | | 141 ± 8
| 10 | 200 ± 12 | 140 ± 6 | 251 ± 3
| 33 | 199 ± 21 | 137 ± 10 | 236 ± 3
| 100 | 183 ± 16 | 127 ± 10 | 206 ± 7
| 200 | | 81 ± 9^b^
| 333 | 0 ± 0^b^ | 0 ± 0^b^ | 120 ± 7^b^
| 833 | 0 ± 0^b^ | | 0 ± 0^b^
Trial summary | | Equivocal | Negative | Negative
Positive control | | 1,681 ± 124 | 1,715 ± 61 | 794 ± 30
Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% hamster S9 | With 30% hamster S9 | With 10% rat S9 | With 30% rat S9
TA98
| 0 | 15 ± 2 | 12 ± 1 | 14 ± 1 | 20 ± 3 | 12 ± 1 | 29 ± 7
| 3.3 | 17 ± 2 | 9 ± 2
| 10 | 14 ± 2 | 8 ± 1 | 17 ± 2 | 18 ± 4 | 15 ± 4 | 21 ± 3
| 33 | 16 ± 4 | 13 ± 3 | 19 ± 4 | 22 ± 2 | 14 ± 1 | 22 ± 1
| 100 | 11 ± 3^b^ | 10 ± 3 | 17 ± 3 | 18 ± 4 | 16 ± 2 | 17 ± 1
| 217 | 3 ± 3^b^ | 0 ± 0^b^
| 333 | | | 10 ± 2^b^ | 17 ± 2 | 10 ± 4^b^ | 20 ± 3
| 833 | | | 0 ± 0^b^ | 7 ± 1^b^ | 0 ± 0^b^ | 3 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control^c^ | | 477 ± 21 | 71 ± 5 | 211 ± 16 | 64 ± 6 | 115 ± 28 | 226 ± 13
TA1535
| 0 | 14 ± 4 | 8 ± 1 | 9 ± 2 | 17 ± 1 | 12 ± 1 | 13 ± 2
| 3.3 | 14 ± 2 | 7 ± 1
| 10 | 10 ± 5 | 9 ± 1 | 11 ± 1 | 15 ± 1 | 8 ± 1 | 18 ± 2
| 33 | 11 ± 1 | 12 ± 2 | 11 ± 1 | 19 ± 3 | 4 ± 0 | 19 ± 4
| 100 | 9 ± 1 | 8 ± 1 | 13 ± 1 | 14 ± 2 | 11 ± 3 | 18 ± 4
| 217 | Toxic | 0 ± 0^b^
| 333 | | | 8 ± 2^b^ | 15 ± 2 | 7 ± 2^b^ | 10 ± 0
| 833 | | | 1 ± 0^b^ | Toxic | 0 ± 0^b^ | Toxic
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 336 ± 15 | 283 ± 12 | 30 ± 7 | 101 ± 3 | 156 ± 11 | 277 ± 17

^a^ Study was performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al.^82^ 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA97), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Administration of Myristicin by Gavage for Three Months^a^

| Dose (mg/kg) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^c^ | PCEs^b ^(%) | P Value^c^
Male
Corn oil^d^ | 0 | 5 | 0.44 ± 0.14 | | 0.24 ± 0.07 | | 1.230 ± 0.08
Myristicin | 10 | 5 | 0.38 ± 0.05 | 0.6132 | 0.18 ± 0.06 | 0.5967 | 1.209 ± 0.05 | 1.0000
| 30 | 5 | 0.42 ± 0.08 | 0.7001 | 0.33 ± 0.04 | 0.4044 | 1.469 ± 0.06 | 0.0545
| 100 | 5 | 0.38 ± 0.04 | 0.7347 | 0.24 ± 0.06 | 0.4319 | 1.372 ± 0.06 | 0.0570
| 300 | 5 | 0.47 ± 0.08 | 0.5263 | 0.42 ± 0.14 | 0.2471 | 1.651 ± 0.09 | 0.0004
| 600 | 5 | 0.75 ± 0.09 | 0.0109 | 0.26 ± 0.05 | 0.2528 | 1.789 ± 0.08 | 0.0001
| | | P = 0.001^e^ | | P = 0.264 | | P = 0.000
Female
Corn oil | 0 | 5 | 0.24 ± 0.09 | | 0.09 ± 0.02 | | 1.012 ± 0.03
Myristicin | 10 | 5 | 0.24 ± 0.02 | 0.5014 | 0.07 ± 0.02 | 0.6367 | 1.053 ± 0.07 | 0.7446
| 30 | 5 | 0.31 ± 0.02 | 0.3737 | 0.14 ± 0.02 | 0.3280 | 1.156 ± 0.08 | 0.2638
| 100 | 5 | 0.24 ± 0.05 | 0.3987 | 0.08 ± 0.02 | 0.3508 | 1.236 ± 0.13 | 0.1049
| 300 | 5 | 0.29 ± 0.04 | 0.3183 | 0.14 ± 0.02 | 0.0647 | 1.256 ± 0.05 | 0.0497
| 600 | 5 | 0.41 ± 0.03 | 0.0139 | 0.23 ± 0.02 | 0.0000 | 1.599 ± 0.11 | 0.0002
| | | P = 0.006 | | P = 0.000 | | P = 0.000

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^83^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant when the one-sided P ≤ 0.025 by Williams’ test. P-values for %PCEs are compared to a two-sided P < 0.05.

^d^ Vehicle control.

^e^ Dose-related trend; significant when compared to one-sided P ≤ 0.025 by linear regression.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Administration of Myristicin by Gavage for Three Months^a^

| Dose (mg/kg) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^c^ | PCEs^b ^(%) | P Value^c^
Male
Corn oil^d^ | 0 | 5 | 2.67 ± 0.23 | | 1.45 ± 0.03 | | 1.490 ± 0.08
Myristicin | 10 | 5 | 2.29 ± 0.12 | 0.8147 | 1.47 ± 0.03 | 0.6573 | 1.439 ± 0.04 | 0.6890
| 30 | 5 | 2.56 ± 0.11 | 0.8854 | 1.45 ± 0.03 | 0.7435 | 1.408 ± 0.04 | 0.6740
| 100 | 5 | 2.34 ± 0.17 | 0.9088 | 1.48 ± 0.02 | 0.7779 | 1.433 ± 0.07 | 0.7185
| 300 | 5 | 2.52 ± 0.15 | 0.8851 | 1.37 ± 0.04 | 0.7941 | 1.206 ± 0.04 | 0.0135
| 600 | 5 | 2.49 ± 0.14 | 0.8944 | 1.39 ± 0.03 | 0.8073 | 0.736 ± 0.07 | 0.0000
| | | P = 0.471^e^ | | P = 0.992 | | P = 0.000
Female
Corn oil | 0 | 5 | 1.87 ± 0.10 | | 1.06 ± 0.02 | | 1.519 ± 0.11
Myristicin | 10 | 5 | 1.82 ± 0.13 | 0.6273 | 1.07 ± 0.02 | 0.5436 | 1.583 ± 0.23 | 1.0000
| 30 | 5 | 2.17 ± 0.04 | 0.7140 | 1.07 ± 0.02 | 0.6268 | 1.428 ± 0.18 | 0.7130
| 100 | 5 | 1.90 ± 0.16 | 0.7487 | 1.09 ± 0.04 | 0.6618 | 1.271 ± 0.15 | 0.2999
| 300 | 5 | 1.58 ± 0.10 | 0.7656 | 1.06 ± 0.03 | 0.6811 | 0.971 ± 0.05 | 0.0380
| 600 | 5 | 1.53 ± 0.20 | 0.7785 | 1.00 ± 0.02 | 0.6939 | 1.149 ± 0.17 | 0.0389
| | | P = 0.997 | | P = 0.984 | | P = 0.016

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^83^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values for PCEs and NCEs are significant when the one-sided P ≤ 0.025 by Williams’ test. P-values for %PCEs are compared to a two-sided P < 0.05.

^d^ Vehicle control.

^e^ Dose-related trend; significant when compared to a one-sided P ≤ 0.025 by linear regression.