# Appendix D Reproductive Tissue Evaluations

Table D-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 100 mg/kg | 300 ppm | 600 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 331 ± 6 | 335 ± 7 | 317 ± 9 | 264 ± 6**
L. Cauda epididymis | 0.1365 ± 0.0033 | 0.1387 ± 0.0028 | 0.1292 ± 0.0045 | 0.1070 ± 0.0031**
L. Epididymis | 0.4090 ± 0.0071 | 0.4104 ± 0.0038 | 0.4008 ± 0.0096 | 0.3444 ± 0.0080**
L. Testis | 1.4464 ± 0.0217 | 1.4943 ± 0.0226 | 1.5092 ± 0.0317 | 1.4106 ± 0.0220
Spermatid measurements
Spermatid heads (10^6^/g testis) | 163.9 ± 10.2 | 167.2 ± 10.4 | 136.6 ± 11.0 | 158.1 ± 19.9
Spermatid heads (10^6^/testis) | 236.90 ± 14.91 | 249.06 ± 14.58 | 205.87 ± 17.18 | 222.92 ± 28.54
Epididymal spermatozoal measurements
Sperm motility (%) | 86.0 ± 0.4 | 85.3 ± 0.5 | 85.0 ± 0.5 | 84.4 ± 0.5
Sperm (10^6^/g cauda epididymis) | 652.9 ± 32.7 | 643.3 ± 39.7 | 612.5 ± 25.3 | 635.8 ± 33.3
Sperm (10^6^/cauda epididymis) | 89.37 ± 5.49 | 88.63 ± 4.42 | 79.11 ± 4.47 | 67.63 ± 3.18**

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ (body, cauda epididymis, and epididymis weights) or Shirley’s (sperm per cauda epididymis) test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s (testis weight) or Dunn’s (spermatid measurements, sperm motility, and sperm per g cauda epididymis) test.

Table D-2 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 100 mg/kg | 300 mg/kg | 600 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 38.8 ± 1.2 | 37.7 ± 0.9 | 34.2 ± 1.1** | 29.3 ± 0.6**
L. Cauda epididymis | 0.0132 ± 0.0006 | 0.0138 ± 0.0007 | 0.0138 ± 0.0007 | 0.0104 ± 0.0006**
L. Epididymis | 0.0409 ± 0.0012 | 0.0414 ± 0.0007 | 0.0401 ± 0.0009 | 0.0337 ± 0.0010**
L. Testis | 0.1118 ± 0.0016 | 0.1110 ± 0.0018 | 0.1147 ± 0.0014 | 0.1045 ± 0.0010**
Spermatid measurements
Spermatid heads (10^6^/g testis) | 190.0 ± 16.2 | 251.4 ± 21.6 | 212.1 ± 10.8 | 177.0 ± 18.5
Spermatid heads (10^6^/testis) | 21.32 ± 1.93 | 27.93 ± 2.45 | 24.32 ± 1.27 | 18.56 ± 1.98
Epididymal spermatozoal measurements
Sperm motility (%) | 85.9 ± 0.6 | 86.4 ± 0.7 | 86.1 ± 0.5 | 84.8 ± 0.4
Sperm (10^6^/g cauda epididymis) | 1,207.5 ± 89.5 | 1,297.7 ± 51.8 | 1,298.5 ± 95.9 | 1,377.2 ± 57.1
Sperm (10^6^/cauda epididymis) | 15.89 ± 1.39 | 17.80 ± 0.82 | 17.84 ± 1.46 | 14.25 ± 0.85

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ (body and epididymis weights) or Dunnett’s (cauda epididymis and testis weights) test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunn’s test (spermatid and epididymal spermatozoal measurements).