# Appendix C Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table C-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 0 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 331 ± 6 | 327 ± 5 | 334 ± 7 | 335 ± 7 | 317 ± 9 | 264 ± 6**
Heart
Absolute | 1.02 ± 0.02 | 1.00 ± 0.02 | 1.01 ± 0.01 | 1.01 ± 0.01 | 1.02 ± 0.03 | 0.94 ± 0.02*
Relative | 3.07 ± 0.05 | 3.07 ± 0.06 | 3.03 ± 0.05 | 3.04 ± 0.06 | 3.22 ± 0.03* | 3.57 ± 0.05**
R. Kidney
Absolute | 1.00 ± 0.03 | 0.97 ± 0.02 | 1.04 ± 0.03 | 1.09 ± 0.04* | 1.15 ± 0.04** | 1.09 ± 0.03**
Relative | 3.00 ± 0.05 | 2.97 ± 0.06 | 3.12 ± 0.07 | 3.27 ± 0.09** | 3.62 ± 0.05** | 4.13 ± 0.07**
Liver
Absolute | 12.61 ± 0.26 | 12.44 ± 0.34 | 13.74 ± 0.35 | 14.42 ± 0.44** | 18.97 ± 0.54** | 21.71 ± 0.66**
Relative | 38.07 ± 0.34 | 38.06 ± 0.73 | 41.20 ± 0.97* | 43.04 ± 0.70** | 59.91 ± 0.78** | 82.39 ± 1.68**
Lung
Absolute | 1.99 ± 0.07 | 1.94 ± 0.08 | 2.01 ± 0.06 | 1.94 ± 0.09 | 1.80 ± 0.08 | 1.79 ± 0.06
Relative | 6.00 ± 0.17 | 5.94 ± 0.27 | 6.02 ± 0.11 | 5.78 ± 0.22 | 5.69 ± 0.19 | 6.81 ± 0.24*
R. Testis
Absolute | 1.394 ± 0.022 | 1.268 ± 0.063 | 1.425 ± 0.015 | 1.434 ± 0.023 | 1.454 ± 0.036 | 1.374 ± 0.027
Relative | 4.212 ± 0.056 | 3.886 ± 0.196 | 4.285 ± 0.111 | 4.295 ± 0.071 | 4.599 ± 0.074* | 5.228 ± 0.099**
Thymus
Absolute | 0.327 ± 0.012 | 0.301 ± 0.013 | 0.327 ± 0.013 | 0.322 ± 0.021 | 0.313 ± 0.014 | 0.220 ± 0.006**
Relative | 0.989 ± 0.035 | 0.922 ± 0.036 | 0.979 ± 0.035 | 0.957 ± 0.055 | 0.989 ± 0.042 | 0.837 ± 0.024*
Female
n | 10 | 10 | 10 | 10 | 10 | 7
Necropsy body wt | 179 ± 4 | 182 ± 3 | 178 ± 4 | 179 ± 2 | 172 ± 2 | 172 ± 7
Heart
Absolute | 0.66 ± 0.02 | 0.65 ± 0.02 | 0.64 ± 0.01 | 0.64 ± 0.01 | 0.66 ± 0.02 | 0.66 ± 0.02
Relative | 3.67 ± 0.08 | 3.57 ± 0.10 | 3.58 ± 0.08 | 3.60 ± 0.04 | 3.81 ± 0.07 | 3.84 ± 0.07
R. Kidney
Absolute | 0.64 ± 0.01 | 0.63 ± 0.02 | 0.62 ± 0.02 | 0.65 ± 0.01 | 0.66 ± 0.01 | 0.69 ± 0.02
Relative | 3.55 ± 0.06 | 3.43 ± 0.04 | 3.51 ± 0.09 | 3.61 ± 0.06 | 3.83 ± 0.04** | 4.03 ± 0.08**
Liver
Absolute | 6.55 ± 0.23 | 6.64 ± 0.18 | 6.81 ± 0.12 | 7.88 ± 0.18** | 10.55 ± 0.29** | 14.70 ± 0.50**
Relative | 36.57 ± 0.97 | 36.47 ± 0.65 | 38.33 ± 1.04 | 44.12 ± 1.10** | 61.34 ± 1.58** | 85.76 ± 1.19**
Lung
Absolute | 1.09 ± 0.05 | 1.24 ± 0.06 | 1.16 ± 0.05 | 1.20 ± 0.02 | 1.18 ± 0.05 | 1.12 ± 0.07
Relative | 6.09 ± 0.20 | 6.82 ± 0.36 | 6.48 ± 0.21 | 6.71 ± 0.17 | 6.86 ± 0.26 | 6.54 ± 0.20
Thymus
Absolute | 0.223 ± 0.005 | 0.221 ± 0.005 | 0.241 ± 0.008 | 0.248 ± 0.010 | 0.217 ± 0.008 | 0.225 ± 0.008
Relative | 1.247 ± 0.027 | 1.219 ± 0.034 | 1.352 ± 0.041 | 1.390 ± 0.056* | 1.257 ± 0.035 | 1.314 ± 0.021

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table C-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 38.8 ± 1.2 | 38.1 ± 1.1 | 38.3 ± 0.8 | 37.7 ± 0.9 | 34.2 ± 1.1** | 29.3 ± 0.6**
Heart
Absolute | 0.18 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.01 | 0.16 ± 0.01**
Relative | 4.72 ± 0.19 | 5.23 ± 0.18 | 5.32 ± 0.14 | 4.80 ± 0.30 | 5.31 ± 0.28 | 5.29 ± 0.19
R. Kidney
Absolute | 0.27 ± 0.01 | 0.26 ± 0.02 | 0.26 ± 0.00 | 0.26 ± 0.01 | 0.23 ± 0.01** | 0.20 ± 0.00**
Relative | 6.96 ± 0.18 | 6.92 ± 0.43 | 6.85 ± 0.13 | 6.80 ± 0.17 | 6.65 ± 0.14 | 6.76 ± 0.08
Liver
Absolute | 1.54 ± 0.05 | 1.57 ± 0.05 | 1.58 ± 0.04 | 1.73 ± 0.04** | 2.32 ± 0.06** | 2.69 ± 0.06**
Relative | 39.67 ± 0.46 | 41.18 ± 0.90 | 41.09 ± 0.47 | 45.97 ± 0.54** | 67.94 ± 1.05** | 91.64 ± 0.79**
Lung
Absolute | 0.28 ± 0.01 | 0.30 ± 0.02 | 0.30 ± 0.01 | 0.25 ± 0.02^b^ | 0.30 ± 0.04 | 0.22 ± 0.01
Relative | 7.30 ± 0.34 | 8.00 ± 0.47 | 7.89 ± 0.34 | 6.72 ± 0.47^b^ | 8.97 ± 1.46 | 7.49 ± 0.30
R. Testis
Absolute | 0.117 ± 0.001 | 0.131 ± 0.016 | 0.119 ± 0.001 | 0.111 ± 0.002 | 0.117 ± 0.002 | 0.111 ± 0.001
Relative | 3.024 ± 0.074 | 3.455 ± 0.448 | 3.106 ± 0.062 | 2.940 ± 0.075 | 3.453 ± 0.090 | 3.790 ± 0.082**
Thymus
Absolute | 0.046 ± 0.003 | 0.046 ± 0.002 | 0.051 ± 0.002 | 0.042 ± 0.002 | 0.041 ± 0.002 | 0.036 ± 0.002**
Relative | 1.208 ± 0.106 | 1.219 ± 0.045 | 1.334 ± 0.059 | 1.119 ± 0.036 | 1.212 ± 0.067 | 1.223 ± 0.058
Female
Necropsy body wt | 28.3 ± 0.8 | 31.0 ± 0.8 | 29.1 ± 1.0 | 27.2 ± 0.6 | 25.3 ± 0.3** | 23.9 ± 0.4**
Heart
Absolute | 0.14 ± 0.01 | 0.15 ± 0.00 | 0.16 ± 0.01 | 0.15 ± 0.01 | 0.13 ± 0.01 | 0.12 ± 0.01*
Relative | 4.85 ± 0.20 | 5.00 ± 0.19 | 5.45 ± 0.20 | 5.40 ± 0.31 | 5.23 ± 0.18 | 4.91 ± 0.19
R. Kidney
Absolute | 0.15 ± 0.00 | 0.17 ± 0.00 | 0.16 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.00
Relative | 5.36 ± 0.09 | 5.35 ± 0.08 | 5.44 ± 0.18 | 5.68 ± 0.15 | 5.81 ± 0.06** | 6.13 ± 0.06**
Liver
Absolute | 1.09 ± 0.02 | 1.29 ± 0.04** | 1.21 ± 0.03** | 1.27 ± 0.04** | 1.76 ± 0.03** | 2.49 ± 0.06**
Relative | 38.77 ± 0.54 | 41.52 ± 0.74* | 41.77 ± 0.56* | 46.64 ± 0.97** | 69.63 ± 1.22** | 103.96 ± 1.23**
Lung
Absolute | 0.24 ± 0.01 | 0.27 ± 0.01 | 0.25 ± 0.01 | 0.28 ± 0.02 | 0.25 ± 0.01 | 0.24 ± 0.01
Relative | 8.69 ± 0.63 | 8.92 ± 0.35 | 8.86 ± 0.48 | 10.24 ± 0.66 | 9.74 ± 0.48 | 9.85 ± 0.53
Thymus
Absolute | 0.049 ± 0.002 | 0.055 ± 0.002 | 0.053 ± 0.002 | 0.044 ± 0.003 | 0.040 ± 0.001** | 0.039 ± 0.002**
Relative | 1.728 ± 0.106 | 1.766 ± 0.049 | 1.833 ± 0.078 | 1.613 ± 0.069 | 1.576 ± 0.043 | 1.632 ± 0.069

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 9.