# Appendix B Clinical Pathology Results

Table B-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Male
Hematology
n
Day 3 | 9 | 9 | 10 | 10 | 10 | 10
Day 22 | 10 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (auto) (%)
Day 3 | 43.0 ± 0.6 | 43.9 ± 0.6 | 43.3 ± 0.5 | 43.0 ± 0.5 | 44.3 ± 0.5 | 45.4 ± 0.6**
Day 22 | 45.1 ± 0.3 | 43.9 ± 0.2 | 45.6 ± 0.5 | 46.2 ± 0.4 | 44.2 ± 0.4 | 42.4 ± 0.9*
Week 14 | 47.3 ± 0.5 | 47.3 ± 0.3 | 46.5 ± 0.4 | 46.9 ± 0.4 | 46.3 ± 0.4 | 46.4 ± 0.3
Manual hematocrit (%)
Day 3 | 43.2 ± 0.4 | 44.6 ± 0.5 | 43.6 ± 0.4^b^ | 43.7 ± 0.4^b^ | 45.3 ± 0.4**^b^ | 46.3 ± 0.5**
Day 22 | 45.3 ± 0.5 | 45.1 ± 0.3 | 46.3 ± 0.4 | 46.4 ± 0.4 | 45.0 ± 0.5 | 43.3 ± 0.7
Week 14 | 47.6 ± 0.5 | 46.7 ± 0.4 | 46.8 ± 0.4 | 47.0 ± 0.4 | 46.3 ± 0.4 | 46.1 ± 0.3
Hemoglobin (g/dL)
Day 3 | 13.5 ± 0.2 | 13.8 ± 0.1 | 13.6 ± 0.1 | 13.6 ± 0.2 | 14.1 ± 0.1** | 14.7 ± 0.1**
Day 22 | 14.1 ± 0.1 | 13.8 ± 0.1 | 14.2 ± 0.1 | 14.3 ± 0.1 | 14.0 ± 0.1 | 13.4 ± 0.3
Week 14 | 15.0 ± 0.1 | 14.8 ± 0.1 | 14.7 ± 0.2 | 14.8 ± 0.1 | 14.6 ± 0.1 | 14.5 ± 0.1**
Erythrocytes (10^6^/μL)
Day 3 | 7.41 ± 0.15 | 7.49 ± 0.09 | 7.43 ± 0.10 | 7.39 ± 0.12 | 7.60 ± 0.09 | 7.90 ± 0.10**
Day 22 | 7.99 ± 0.09 | 7.78 ± 0.04 | 8.05 ± 0.10 | 8.16 ± 0.07 | 7.81 ± 0.07 | 7.70 ± 0.16
Week 14 | 9.25 ± 0.11 | 9.19 ± 0.07 | 9.11 ± 0.09 | 9.07 ± 0.07 | 9.00 ± 0.07 | 9.13 ± 0.06
Reticulocytes (10^3^/μL)
Day 3 | 424 ± 31 | 405 ± 25 | 450 ± 31 | 414 ± 22 | 412 ± 27 | 344 ± 14
Day 22 | 275 ± 8 | 269 ± 8 | 287 ± 7 | 285 ± 6 | 289 ± 7 | 319 ± 29
Week 14 | 186 ± 6 | 193 ± 8 | 208 ± 5* | 203 ± 5* | 226 ± 6** | 254 ± 6**
Mean cell volume (fL)
Day 3 | 58.2 ± 0.5 | 58.6 ± 0.3 | 58.3 ± 0.4 | 58.3 ± 0.4 | 58.3 ± 0.5 | 57.5 ± 0.3
Day 22 | 56.5 ± 0.4 | 56.4 ± 0.2 | 56.6 ± 0.3 | 56.7 ± 0.2 | 56.6 ± 0.3 | 55.1 ± 0.2**
Week 14 | 51.1 ± 0.1 | 51.5 ± 0.2 | 51.0 ± 0.1 | 51.7 ± 0.1* | 51.5 ± 0.2 | 50.8 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 18.3 ± 0.1 | 18.5 ± 0.1 | 18.4 ± 0.1 | 18.5 ± 0.1 | 18.6 ± 0.1 | 18.6 ± 0.1
Day 22 | 17.6 ± 0.1 | 17.7 ± 0.1 | 17.7 ± 0.1 | 17.6 ± 0.1 | 18.0 ± 0.1 | 17.4 ± 0.1
Week 14 | 16.2 ± 0.1 | 16.1 ± 0.0 | 16.2 ± 0.1 | 16.3 ± 0.0 | 16.2 ± 0.1 | 15.8 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 31.4 ± 0.2 | 31.6 ± 0.1 | 31.5 ± 0.2 | 31.7 ± 0.2 | 31.9 ± 0.2 | 32.4 ± 0.2**
Day 22 | 31.2 ± 0.1 | 31.4 ± 0.1 | 31.3 ± 0.1 | 31.0 ± 0.1 | 31.7 ± 0.1* | 31.5 ± 0.2
Week 14 | 31.7 ± 0.2 | 31.3 ± 0.1 | 31.7 ± 0.2 | 31.5 ± 0.1 | 31.5 ± 0.2 | 31.1 ± 0.1
Platelets (10^3^/μL)
Day 3 | 1,078 ± 27 | 1,025 ± 36 | 1,073 ± 32 | 1,030 ± 23 | 944 ± 25** | 1,021 ± 40
Day 22 | 817 ± 17 | 823 ± 21 | 784 ± 34 | 779 ± 15 | 829 ± 28 | 935 ± 28*
Week 14 | 626 ± 14 | 633 ± 22 | 670 ± 12 | 656 ± 18 | 701 ± 20** | 785 ± 31**
Leukocytes (10^3^/μL)
Day 3 | 8.27 ± 0.42 | 8.87 ± 0.25 | 8.60 ± 0.20 | 8.67 ± 0.32 | 8.01 ± 0.47 | 7.34 ± 0.74
Day 22 | 7.81 ± 0.34 | 8.49 ± 0.30 | 8.76 ± 0.44 | 7.83 ± 0.38 | 8.92 ± 0.23 | 8.16 ± 0.23
Week 14 | 9.53 ± 0.50 | 8.96 ± 0.48 | 9.93 ± 0.23 | 9.29 ± 0.28 | 10.65 ± 0.51 | 9.31 ± 0.30
Segmented neutrophils (10^3^/μL)
Day 3 | 1.46 ± 0.08 | 1.48 ± 0.07 | 1.60 ± 0.10 | 1.51 ± 0.07 | 1.51 ± 0.11 | 1.36 ± 0.09
Day 22 | 1.54 ± 0.08 | 1.52 ± 0.11 | 1.64 ± 0.11 | 1.72 ± 0.09 | 1.77 ± 0.11 | 1.62 ± 0.09
Week 14 | 1.53 ± 0.06 | 1.98 ± 0.20 | 1.85 ± 0.10 | 1.53 ± 0.07 | 1.96 ± 0.10* | 1.90 ± 0.08*
Lymphocytes (10^3^/μL)
Day 3 | 6.44 ± 0.37 | 6.96 ± 0.20 | 6.60 ± 0.18 | 6.79 ± 0.29 | 6.16 ± 0.37 | 5.69 ± 0.66
Day 22 | 5.96 ± 0.30 | 6.62 ± 0.30 | 6.78 ± 0.39 | 5.81 ± 0.29 | 6.77 ± 0.23 | 6.19 ± 0.22
Week 14 | 7.66 ± 0.45 | 6.64 ± 0.43 | 7.74 ± 0.19 | 7.48 ± 0.24 | 8.35 ± 0.45 | 7.04 ± 0.25
Monocytes (10^3^/μL)
Day 3 | 0.30 ± 0.02 | 0.33 ± 0.02 | 0.33 ± 0.02 | 0.29 ± 0.02 | 0.28 ± 0.03 | 0.24 ± 0.03
Day 22 | 0.20 ± 0.03 | 0.24 ± 0.01 | 0.25 ± 0.03 | 0.20 ± 0.03 | 0.27 ± 0.02 | 0.29 ± 0.02*
Week 14 | 0.23 ± 0.01 | 0.22 ± 0.02 | 0.23 ± 0.01 | 0.19 ± 0.01 | 0.26 ± 0.02 | 0.30 ± 0.03
Basophils (10^3^/μL)
Day 3 | 0.017 ± 0.002 | 0.022 ± 0.006 | 0.018 ± 0.002 | 0.018 ± 0.002 | 0.018 ± 0.002 | 0.013 ± 0.003
Day 22 | 0.044 ± 0.009 | 0.045 ± 0.007 | 0.038 ± 0.007 | 0.024 ± 0.003 | 0.038 ± 0.007 | 0.026 ± 0.002
Week 14 | 0.031 ± 0.003 | 0.025 ± 0.003 | 0.030 ± 0.003 | 0.026 ± 0.003 | 0.026 ± 0.004 | 0.026 ± 0.002
Eosinophils (10^3^/μL)
Day 3 | 0.05 ± 0.00 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.00 | 0.04 ± 0.00*
Day 22 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.08 ± 0.02 | 0.07 ± 0.02 | 0.03 ± 0.00**
Week 14 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.07 ± 0.00 | 0.06 ± 0.01** | 0.04 ± 0.00**
Clinical Chemistry
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 22 | 10 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 12.9 ± 0.4^c^ | 13.5 ± 0.7 | 13.3 ± 0.3 | 13.8 ± 0.6^b^ | 14.2 ± 0.8 | 17.0 ± 0.8**^c^
Day 22 | 10.1 ± 0.4 | 10.1 ± 0.5 | 10.2 ± 0.5 | 13.1 ± 0.8* | 12.0 ± 0.4* | 12.3 ± 0.6*
Week 14 | 13.3 ± 0.6 | 13.1 ± 0.7 | 13.4 ± 0.4 | 14.1 ± 0.6 | 14.0 ± 0.4 | 15.8 ± 0.8*
Creatinine (mg/dL)
Day 3 | 0.61 ± 0.01^b^ | 0.61 ± 0.01 | 0.60 ± 0.00 | 0.60 ± 0.00^b^ | 0.61 ± 0.01 | 0.65 ± 0.03
Day 22 | 0.62 ± 0.01 | 0.60 ± 0.00 | 0.61 ± 0.01 | 0.61 ± 0.02 | 0.61 ± 0.01 | 0.62 ± 0.01
Week 14 | 0.70 ± 0.01 | 0.74 ± 0.04 | 0.71 ± 0.01 | 0.73 ± 0.02 | 0.75 ± 0.02* | 0.76 ± 0.02*
Glucose (mg/dL)
Day 3 | 140 ± 2^c^ | 141 ± 3 | 137 ± 2 | 136 ± 1 | 135 ± 3 | 128 ± 6^c^
Day 22 | 139 ± 2 | 139 ± 3 | 140 ± 2 | 136 ± 3 | 137 ± 3 | 140 ± 2
Week 14 | 133 ± 2 | 133 ± 2 | 130 ± 2 | 133 ± 2 | 131 ± 2 | 137 ± 8
Total protein (g/dL)
Day 3 | 5.5 ± 0.1^c^ | 5.7 ± 0.1 | 5.5 ± 0.1 | 5.5 ± 0.1^b^ | 5.4 ± 0.1 | 5.4 ± 0.1^c^
Day 22 | 6.1 ± 0.1 | 5.8 ± 0.1* | 6.0 ± 0.1 | 6.0 ± 0.1 | 6.1 ± 0.1 | 6.4 ± 0.1
Week 14 | 7.2 ± 0.1 | 7.1 ± 0.1 | 7.2 ± 0.1 | 7.2 ± 0.1 | 7.7 ± 0.1** | 8.0 ± 0.1**
Albumin (g/dL)
Day 3 | 3.9 ± 0.1 | 4.0 ± 0.0 | 3.9 ± 0.0 | 3.9 ± 0.1 | 3.8 ± 0.1 | 3.9 ± 0.0
Day 22 | 4.3 ± 0.0 | 4.1 ± 0.0 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.1 ± 0.0 | 4.4 ± 0.1
Week 14 | 4.6 ± 0.0 | 4.5 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.8 ± 0.0* | 5.0 ± 0.0**
Cholesterol (mg/dL)
Day 3 | 88 ± 2 | 90 ± 2 | 92 ± 2 | 101 ± 3** | 108 ± 4** | 103 ± 3**^b^
Day 22 | 79 ± 1 | 73 ± 1 | 79 ± 1 | 81 ± 1 | 88 ± 2** | 122 ± 4**
Week 14 | 79 ± 1 | 77 ± 2 | 83 ± 2 | 85 ± 1* | 113 ± 2** | 149 ± 3**
Triglycerides (mg/dL)
Day 3 | 107 ± 8^b^ | 135 ± 28 | 110 ± 9 | 115 ± 4 | 127 ± 8 | 266 ± 34**^c^
Day 22 | 98 ± 8 | 101 ± 6 | 112 ± 8 | 80 ± 12 | 121 ± 10 | 179 ± 17**
Week 14 | 120 ± 9 | 113 ± 8 | 135 ± 10 | 128 ± 9 | 164 ± 9** | 192 ± 20**
Alanine aminotransferase (IU/L)
Day 3 | 64 ± 3 | 66 ± 4 | 64 ± 2 | 67 ± 2 | 72 ± 3* | 78 ± 5*
Day 22 | 49 ± 1 | 51 ± 2 | 51 ± 1 | 55 ± 2* | 56 ± 1** | 62 ± 2**
Week 14 | 64 ± 2 | 61 ± 3 | 60 ± 3 | 58 ± 2 | 60 ± 2 | 84 ± 3*
Alkaline phosphatase (IU/L)
Day 3 | 641 ± 29^d^ | 669 ± 24 | 623 ± 26^c^ | 616 ± 17^d^ | 661 ± 25^b^ | 537 ± 24^b^
Day 22 | 453 ± 10 | 435 ± 6 | 447 ± 12 | 399 ± 16* | 377 ± 7** | 330 ± 11**
Week 14 | 249 ± 9 | 265 ± 7 | 261 ± 5 | 249 ± 6 | 232 ± 6 | 223 ± 6*
Creatine kinase (IU/L)
Day 3 | 742 ± 186^b^ | 388 ± 43 | 526 ± 80 | 553 ± 108 | 536 ± 117 | 647 ± 118^d^
Day 22 | 335 ± 71 | 411 ± 112^b^ | 479 ± 135 | 318 ± 44^b^ | 324 ± 82 | 310 ± 39^c^
Week 14 | 476 ± 64^b^ | 346 ± 38 | 535 ± 51 | 555 ± 108 | 469 ± 49 | 468 ± 43
Sorbitol dehydrogenase (IU/L)
Day 3 | 10 ± 0^b^ | 11 ± 0 | 11 ± 0 | 10 ± 0^b^ | 12 ± 1** | 10 ± 1^b^
Day 22 | 14 ± 1 | 13 ± 1 | 13 ± 0 | 13 ± 1 | 12 ± 1 | 15 ± 1
Week 14 | 16 ± 1 | 16 ± 1 | 14 ± 1 | 15 ± 1 | 15 ± 1 | 22 ± 1**
Bile acids (μmol/L)
Day 3 | 15.4 ± 2.8^b^ | 20.1 ± 2.8 | 15.0 ± 2.6 | 15.4 ± 2.4^b^ | 18.1 ± 2.4 | 19.2 ± 2.7^b^
Day 22 | 12.2 ± 1.9 | 19.3 ± 1.3 | 13.5 ± 1.8 | 10.9 ± 1.2 | 6.9 ± 0.9* | 7.1 ± 1.0*
Week 14 | 8.2 ± 1.4 | 10.7 ± 1.3 | 10.2 ± 1.0 | 9.8 ± 1.1 | 6.7 ± 0.5 | 6.5 ± 1.2
Female
Hematology
n
Day 3 | 10 | 9 | 10 | 9 | 10 | 9
Day 22 | 8 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 9 | 10 | 10 | 10 | 7
Hematocrit (auto) (%)
Day 3 | 45.4 ± 0.4 | 45.5 ± 0.5 | 45.2 ± 0.6 | 46.3 ± 0.9 | 45.0 ± 0.3 | 46.1 ± 0.8
Day 22 | 47.2 ± 0.7 | 46.1 ± 0.4 | 45.8 ± 0.5 | 46.2 ± 0.3 | 45.5 ± 0.5* | 44.0 ± 0.4**
Week 14 | 45.7 ± 0.5 | 46.3 ± 0.2 | 45.3 ± 0.2 | 45.9 ± 0.4 | 44.2 ± 0.4** | 44.6 ± 0.5*
Manual hematocrit (%)
Day 3 | 45.2 ± 0.6^b^ | 45.3 ± 0.5 | 45.1 ± 0.5 | 45.4 ± 0.8^d^ | 45.1 ± 0.5 | 46.1 ± 0.7
Day 22 | 47.8 ± 0.4 | 46.4 ± 0.4 | 46.6 ± 0.4 | 46.3 ± 0.4* | 46.4 ± 0.5* | 44.3 ± 0.5**
Week 14 | 46.9 ± 0.4 | 47.3 ± 0.3 | 46.6 ± 0.2 | 47.1 ± 0.2 | 45.9 ± 0.3 | 46.3 ± 0.6
Hemoglobin (g/dL)
Day 3 | 14.7 ± 0.1 | 14.7 ± 0.2 | 14.4 ± 0.2 | 14.9 ± 0.3 | 14.5 ± 0.1 | 15.2 ± 0.2
Day 22 | 15.4 ± 0.3 | 15.1 ± 0.1 | 14.9 ± 0.2 | 15.0 ± 0.1 | 14.8 ± 0.2* | 14.1 ± 0.1**
Week 14 | 14.7 ± 0.1 | 14.9 ± 0.1 | 14.7 ± 0.0 | 14.6 ± 0.1 | 14.2 ± 0.1** | 14.0 ± 0.2**
Erythrocytes (10^6^/μL)
Day 3 | 7.97 ± 0.08 | 7.99 ± 0.12 | 7.87 ± 0.08 | 8.08 ± 0.17 | 7.90 ± 0.08 | 8.18 ± 0.11
Day 22 | 8.62 ± 0.14 | 8.37 ± 0.11 | 8.29 ± 0.09* | 8.38 ± 0.07* | 8.17 ± 0.08** | 8.10 ± 0.08**
Week 14 | 8.39 ± 0.10 | 8.51 ± 0.06 | 8.37 ± 0.04 | 8.42 ± 0.06 | 8.19 ± 0.06 | 8.55 ± 0.11
Reticulocytes (10^3^/μL)
Day 3 | 260 ± 16 | 293 ± 24 | 323 ± 20 | 291 ± 32 | 284 ± 23 | 237 ± 16
Day 22 | 167 ± 9 | 167 ± 3 | 159 ± 8 | 186 ± 7 | 177 ± 3 | 240 ± 12**
Week 14 | 192 ± 6 | 197 ± 11 | 202 ± 9 | 217 ± 14 | 197 ± 6 | 213 ± 9
Mean cell volume (fL)
Day 3 | 56.9 ± 0.4 | 57.0 ± 0.5 | 57.4 ± 0.4 | 57.3 ± 0.6 | 57.0 ± 0.5 | 56.3 ± 0.5
Day 22 | 54.8 ± 0.2 | 55.1 ± 0.4 | 55.3 ± 0.2 | 55.2 ± 0.3 | 55.7 ± 0.3 | 54.3 ± 0.3
Week 14 | 54.4 ± 0.2 | 54.4 ± 0.2 | 54.2 ± 0.1 | 54.5 ± 0.1 | 54.1 ± 0.2 | 52.1 ± 0.2**
Mean cell hemoglobin (pg)
Day 3 | 18.4 ± 0.1 | 18.3 ± 0.1 | 18.3 ± 0.1 | 18.4 ± 0.1 | 18.4 ± 0.1 | 18.6 ± 0.1
Day 22 | 17.9 ± 0.1 | 18.0 ± 0.1 | 18.0 ± 0.1 | 17.9 ± 0.1 | 18.1 ± 0.1 | 17.4 ± 0.1*
Week 14 | 17.5 ± 0.1 | 17.5 ± 0.1 | 17.5 ± 0.1 | 17.4 ± 0.0 | 17.4 ± 0.1 | 16.4 ± 0.1**
Mean cell hemoglobin concentration (g/dL)
Day 3 | 32.3 ± 0.2 | 32.2 ± 0.1 | 31.9 ± 0.2 | 32.2 ± 0.3 | 32.2 ± 0.1 | 32.9 ± 0.3
Day 22 | 32.6 ± 0.2 | 32.7 ± 0.3 | 32.6 ± 0.1 | 32.4 ± 0.1 | 32.5 ± 0.2 | 32.0 ± 0.1*
Week 14 | 32.2 ± 0.1 | 32.2 ± 0.1 | 32.3 ± 0.1 | 31.9 ± 0.1 | 32.1 ± 0.1 | 31.4 ± 0.1**
Platelets (10^3^/μL)
Day 3 | 892 ± 23 | 950 ± 26 | 924 ± 57 | 834 ± 75 | 937 ± 22 | 935 ± 59
Day 22 | 709 ± 25 | 647 ± 48 | 766 ± 11 | 717 ± 22 | 685 ± 23 | 791 ± 24
Week 14 | 716 ± 21 | 665 ± 28 | 689 ± 24 | 662 ± 14 | 690 ± 11 | 743 ± 12
Leukocytes (10^3^/μL)
Day 3 | 9.04 ± 0.39 | 9.24 ± 0.51 | 9.27 ± 0.37 | 8.54 ± 0.38 | 9.02 ± 0.46 | 8.38 ± 0.79
Day 22 | 8.53 ± 0.52 | 8.41 ± 0.36 | 8.26 ± 0.37 | 7.80 ± 0.45 | 8.15 ± 0.51 | 8.71 ± 0.48
Week 14 | 7.67 ± 0.62 | 7.40 ± 0.47 | 8.04 ± 0.32 | 7.59 ± 0.29 | 8.36 ± 0.46 | 8.52 ± 0.27
Segmented neutrophils (10^3^/μL)
Day 3 | 1.57 ± 0.08 | 1.47 ± 0.12 | 1.59 ± 0.15 | 1.36 ± 0.11 | 1.47 ± 0.09 | 1.46 ± 0.10
Day 22 | 1.69 ± 0.10 | 1.58 ± 0.13 | 1.59 ± 0.06 | 1.57 ± 0.10 | 1.79 ± 0.22 | 2.00 ± 0.17
Week 14 | 1.90 ± 0.18 | 1.60 ± 0.15 | 1.62 ± 0.07 | 1.56 ± 0.06 | 1.69 ± 0.13 | 1.86 ± 0.12
Lymphocytes (10^3^/μL)
Day 3 | 7.06 ± 0.38 | 7.31 ± 0.43 | 7.21 ± 0.33 | 6.77 ± 0.31 | 7.16 ± 0.38 | 6.53 ± 0.75
Day 22 | 6.45 ± 0.50 | 6.48 ± 0.29 | 6.34 ± 0.31 | 5.88 ± 0.41 | 5.98 ± 0.33 | 6.33 ± 0.41
Week 14 | 5.47 ± 0.49 | 5.51 ± 0.32 | 6.12 ± 0.28 | 5.74 ± 0.26 | 6.39 ± 0.36 | 6.36 ± 0.17
Monocytes (10^3^/μL)
Day 3 | 0.32 ± 0.02 | 0.33 ± 0.04 | 0.34 ± 0.02 | 0.28 ± 0.02 | 0.30 ± 0.03 | 0.29 ± 0.04
Day 22 | 0.25 ± 0.02 | 0.22 ± 0.02 | 0.22 ± 0.02 | 0.20 ± 0.02 | 0.26 ± 0.02 | 0.29 ± 0.02
Week 14 | 0.18 ± 0.02 | 0.16 ± 0.02 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.19 ± 0.02 | 0.21 ± 0.01
Basophils (10^3^/μL)
Day 3 | 0.020 ± 0.001 | 0.029 ± 0.004 | 0.021 ± 0.002 | 0.023 ± 0.002 | 0.025 ± 0.003 | 0.019 ± 0.004
Day 22 | 0.026 ± 0.004 | 0.033 ± 0.004 | 0.024 ± 0.002 | 0.032 ± 0.006 | 0.027 ± 0.003 | 0.023 ± 0.004
Week 14 | 0.029 ± 0.005 | 0.027 ± 0.006 | 0.031 ± 0.004 | 0.024 ± 0.004 | 0.022 ± 0.004 | 0.017 ± 0.002
Eosinophils (10^3^/μL)
Day 3 | 0.07 ± 0.01 | 0.11 ± 0.03 | 0.11 ± 0.03 | 0.11 ± 0.02 | 0.07 ± 0.01 | 0.07 ± 0.01
Day 22 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.08 ± 0.01 | 0.10 ± 0.02 | 0.10 ± 0.02 | 0.08 ± 0.02
Week 14 | 0.08 ± 0.01 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.06 ± 0.01* | 0.06 ± 0.00*
Clinical Chemistry
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 22 | 9 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 7
Urea nitrogen (mg/dL)
Day 3 | 13.2 ± 0.7^b^ | 14.0 ± 0.8 | 13.7 ± 0.4 | 14.2 ± 0.9 | 12.8 ± 0.6 | 16.6 ± 1.2^b^
Day 22 | 13.1 ± 0.9 | 12.9 ± 0.6 | 11.5 ± 0.3 | 12.6 ± 0.6 | 13.9 ± 0.7 | 13.2 ± 0.5
Week 14 | 13.3 ± 0.7 | 12.6 ± 0.4 | 14.7 ± 0.6 | 13.1 ± 0.2 | 13.9 ± 0.5 | 13.1 ± 1.1
Creatinine (mg/dL)
Day 3 | 0.61 ± 0.01 | 0.60 ± 0.00 | 0.61 ± 0.01 | 0.63 ± 0.02 | 0.60 ± 0.00 | 0.67 ± 0.02**
Day 22 | 0.61 ± 0.01 | 0.62 ± 0.01 | 0.59 ± 0.01 | 0.62 ± 0.01 | 0.61 ± 0.01 | 0.63 ± 0.02
Week 14 | 0.70 ± 0.00 | 0.73 ± 0.02 | 0.71 ± 0.01 | 0.71 ± 0.01 | 0.70 ± 0.00 | 0.71 ± 0.03
Glucose (mg/dL)
Day 3 | 127 ± 2 | 128 ± 3 | 137 ± 6 | 129 ± 2 | 122 ± 2 | 128 ± 6
Day 22 | 143 ± 4 | 150 ± 4 | 135 ± 3 | 134 ± 2 | 138 ± 3 | 139 ± 3
Week 14 | 126 ± 3 | 120 ± 2 | 124 ± 4 | 128 ± 4 | 127 ± 4 | 127 ± 4
Total protein (g/dL)
Day 3 | 5.7 ± 0.1^b^ | 5.8 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.5 ± 0.0* | 5.5 ± 0.1*
Day 22 | 6.1 ± 0.1 | 6.1 ± 0.1 | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.6 ± 0.1**
Week 14 | 7.0 ± 0.1 | 7.3 ± 0.1 | 7.2 ± 0.1 | 7.2 ± 0.1 | 7.7 ± 0.1** | 7.9 ± 0.1**
Albumin (g/dL)
Day 3 | 4.1 ± 0.1 | 4.3 ± 0.1 | 4.1 ± 0.1 | 4.2 ± 0.1 | 4.0 ± 0.1 | 4.0 ± 0.1
Day 22 | 4.5 ± 0.1 | 4.4 ± 0.0 | 4.5 ± 0.1 | 4.5 ± 0.0 | 4.5 ± 0.0 | 4.5 ± 0.1
Week 14 | 4.8 ± 0.1 | 5.0 ± 0.1 | 4.9 ± 0.1 | 4.8 ± 0.1 | 5.0 ± 0.1** | 5.1 ± 0.0**
Cholesterol (mg/dL)
Day 3 | 90 ± 2 | 90 ± 3 | 98 ± 2* | 99 ± 2** | 109 ± 3** | 108 ± 4**
Day 22 | 88 ± 8 | 84 ± 4 | 86 ± 1 | 97 ± 2** | 138 ± 2** | 185 ± 4**
Week 14 | 77 ± 2 | 84 ± 3* | 87 ± 1** | 98 ± 2** | 140 ± 3** | 166 ± 6**
Triglycerides (mg/dL)
Day 3 | 95 ± 5 | 85 ± 5 | 78 ± 3 | 86 ± 8 | 102 ± 8 | 209 ± 21**
Day 22 | 72 ± 8 | 67 ± 6 | 54 ± 5 | 56 ± 8 | 61 ± 5 | 94 ± 8
Week 14 | 50 ± 7 | 56 ± 4 | 53 ± 5 | 46 ± 4 | 67 ± 10 | 69 ± 5*
Alanine aminotransferase (IU/L)
Day 3 | 52 ± 1 | 62 ± 3** | 58 ± 2* | 61 ± 2** | 68 ± 2** | 75 ± 3**
Day 22 | 43 ± 2 | 42 ± 2 | 41 ± 1 | 43 ± 1 | 49 ± 1** | 57 ± 3**
Week 14 | 52 ± 2 | 56 ± 4 | 50 ± 2 | 47 ± 2 | 50 ± 2 | 73 ± 4*
Alkaline phosphatase (IU/L)
Day 3 | 510 ± 10 | 555 ± 19 | 532 ± 13 | 541 ± 23 | 508 ± 12 | 488 ± 19
Day 22 | 374 ± 5 | 366 ± 6 | 345 ± 6** | 352 ± 7* | 331 ± 6** | 333 ± 10**
Week 14 | 261 ± 6 | 267 ± 5 | 262 ± 6 | 223 ± 7** | 193 ± 6** | 246 ± 12*
Creatine kinase (IU/L)
Day 3 | 422 ± 107 | 648 ± 122^b^ | 762 ± 292 | 682 ± 119 | 746 ± 171 | 877 ± 191
Day 22 | 771 ± 399 | 565 ± 176 | 314 ± 78 | 425 ± 116 | 370 ± 95 | 1,260 ± 406
Week 14 | 319 ± 64 | 454 ± 106 | 315 ± 66 | 373 ± 56 | 574 ± 131 | 320 ± 49
Sorbitol dehydrogenase (IU/L)
Day 3 | 12 ± 1 | 10 ± 1 | 12 ± 1 | 12 ± 1 | 12 ± 1 | 13 ± 2
Day 22 | 11 ± 1 | 11 ± 1 | 11 ± 0 | 15 ± 1* | 18 ± 0** | 16 ± 1**
Week 14 | 13 ± 1 | 14 ± 1 | 13 ± 1 | 15 ± 1 | 16 ± 1** | 29 ± 2**
Bile acids (µmol/L)
Day 3 | 10.4 ± 1.5 | 13.2 ± 1.8 | 13.6 ± 1.6 | 12.5 ± 1.5 | 16.5 ± 1.7* | 9.3 ± 0.9
Day 22 | 15.8 ± 2.4 | 13.4 ± 2.2 | 12.0 ± 1.3 | 9.4 ± 1.2 | 9.7 ± 0.5 | 11.0 ± 1.8
Week 14 | 13.5 ± 2.5 | 15.5 ± 2.1 | 14.1 ± 1.9 | 11.7 ± 1.5 | 11.2 ± 1.0 | 11.0 ± 0.9

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 8.

^d^ n = 7.

Table B-2 Hematology Data for Mice in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Male
n | 10 | 9 | 10 | 9 | 10 | 10
Hematocrit (auto) (%) | 50.1 ± 0.6 | 50.0 ± 0.7 | 49.7 ± 0.5 | 48.2 ± 0.3 | 49.1 ± 0.6 | 48.0 ± 0.6*
Manual hematocrit (%) | 50.3 ± 0.6 | 50.1 ± 0.7 | 50.1 ± 0.4 | 49.3 ± 0.4 | 50.1 ± 0.7 | 48.8 ± 0.5
Hemoglobin (g/dL) | 16.1 ± 0.2 | 16.1 ± 0.2 | 16.1 ± 0.2 | 15.5 ± 0.1 | 16.0 ± 0.3 | 15.6 ± 0.2
Erythrocytes (10^6^/µL) | 10.72 ± 0.11 | 10.72 ± 0.18 | 10.70 ± 0.11 | 10.25 ± 0.06** | 10.48 ± 0.14* | 10.40 ± 0.15*
Reticulocytes (10^3^/µL) | 267 ± 6 | 274 ± 9 | 259 ± 6 | 261 ± 9 | 220 ± 8** | 169 ± 21**
Mean cell volume (fL) | 46.8 ± 0.2 | 46.6 ± 0.2 | 46.4 ± 0.1 | 47.0 ± 0.1 | 46.9 ± 0.1 | 46.2 ± 0.2
Mean cell hemoglobin (pg) | 15.1 ± 0.1 | 15.0 ± 0.1 | 15.0 ± 0.0 | 15.1 ± 0.1 | 15.3 ± 0.1 | 15.0 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.2 ± 0.2 | 32.2 ± 0.1 | 32.3 ± 0.1 | 32.2 ± 0.1 | 32.6 ± 0.2 | 32.5 ± 0.2
Platelets (10^3^/µL) | 796 ± 56 | 775 ± 44 | 785 ± 26 | 998 ± 41** | 1,076 ± 52** | 1,046 ± 42**
Leukocytes (10^3^/µL) | 5.68 ± 0.22 | 4.61 ± 0.26 | 5.87 ± 0.84 | 5.61 ± 0.26 | 7.36 ± 0.39* | 8.86 ± 0.60**
Segmented neutrophils (10^3^/µL) | 0.80 ± 0.04 | 0.74 ± 0.10 | 0.85 ± 0.09 | 0.93 ± 0.07 | 1.24 ± 0.14** | 2.12 ± 0.30**
Lymphocytes (10^3^/µL) | 4.66 ± 0.19 | 3.68 ± 0.17 | 4.83 ± 0.72 | 4.48 ± 0.21 | 5.80 ± 0.29 | 6.36 ± 0.36*
Monocytes (10^3^/µL) | 0.10 ± 0.02 | 0.08 ± 0.02 | 0.09 ± 0.02 | 0.08 ± 0.02 | 0.13 ± 0.02 | 0.18 ± 0.04
Basophils (10^3^/µL) | 0.006 ± 0.002 | 0.002 ± 0.001 | 0.007 ± 0.006 | 0.006 ± 0.002 | 0.011 ± 0.003 | 0.012 ± 0.003
Eosinophils (10^3^/µL) | 0.13 ± 0.02 | 0.10 ± 0.02 | 0.09 ± 0.05 | 0.12 ± 0.02 | 0.18 ± 0.04 | 0.19 ± 0.03
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (auto) (%) | 46.9 ± 0.6 | 46.5 ± 0.4 | 46.2 ± 0.3 | 48.7 ± 0.5 | 47.0 ± 0.6 | 47.2 ± 0.6
Manual hematocrit (%) | 48.1 ± 0.7 | 47.8 ± 0.5 | 47.6 ± 0.4 | 49.4 ± 0.6^b^ | 48.3 ± 0.5 | 48.1 ± 0.8
Hemoglobin (g/dL) | 15.5 ± 0.2 | 15.4 ± 0.1 | 15.1 ± 0.1 | 16.1 ± 0.2 | 15.5 ± 0.2 | 15.4 ± 0.2
Erythrocytes (10^6^/µL) | 10.14 ± 0.12 | 9.87 ± 0.09 | 9.83 ± 0.08 | 10.35 ± 0.11 | 10.05 ± 0.10 | 10.21 ± 0.14
Reticulocytes (10^3^/µL) | 271 ± 9 | 260 ± 17 | 265 ± 12 | 244 ± 17 | 198 ± 6** | 209 ± 12**
Mean cell volume (fL) | 46.3 ± 0.2 | 47.1 ± 0.2* | 46.9 ± 0.2 | 47.0 ± 0.1* | 46.7 ± 0.2 | 46.2 ± 0.1
Mean cell hemoglobin (pg) | 15.3 ± 0.1 | 15.6 ± 0.1** | 15.4 ± 0.1 | 15.5 ± 0.1 | 15.4 ± 0.1 | 15.1 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 33.0 ± 0.2 | 33.1 ± 0.1 | 32.7 ± 0.1 | 33.0 ± 0.1 | 33.0 ± 0.2 | 32.6 ± 0.2
Platelets (10^3^/µL) | 769 ± 48 | 730 ± 50 | 764 ± 34 | 708 ± 33 | 790 ± 55 | 852 ± 41
Leukocytes (10^3^/µL) | 5.16 ± 0.53 | 3.79 ± 0.12 | 4.16 ± 0.24 | 5.46 ± 0.27 | 6.12 ± 0.35 | 7.75 ± 0.76*
Segmented neutrophils (10^3^/µL) | 0.56 ± 0.08 | 0.52 ± 0.05 | 0.61 ± 0.08 | 0.72 ± 0.08 | 0.89 ± 0.08** | 1.43 ± 0.23**
Lymphocytes (10^3^/µL) | 4.40 ± 0.47 | 3.19 ± 0.11 | 3.40 ± 0.19 | 4.52 ± 0.18 | 5.04 ± 0.32 | 5.97 ± 0.67
Monocytes (10^3^/µL) | 0.07 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.11 ± 0.03 | 0.09 ± 0.01 | 0.16 ± 0.02**
Basophils (10^3^/µL) | 0.005 ± 0.002 | 0.002 ± 0.001 | 0.004 ± 0.002 | 0.007 ± 0.003 | 0.004 ± 0.002 | 0.011 ± 0.004
Eosinophils (10^3^/µL) | 0.12 ± 0.02 | 0.03 ± 0.01* | 0.08 ± 0.02 | 0.12 ± 0.03 | 0.09 ± 0.02 | 0.19 ± 0.03

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.