# Appendix A Summary of Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Male Rats in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | – | – | – | – | – | 1 (10%)
Intestine large, cecum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (0) | (0) | (0) | (0) | (10)
Parasite metazoan | – | – | – | – | – | 1 (10%)
Intestine large, rectum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, duodenum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Fatty change | – | – | – | – | 10 (100%) | 10 (100%)
Hepatodiaphragmatic nodule | 1 (10%) | 1 (10%) | 1 (10%) | 3 (30%) | – | 1 (10%)
Mixed cell focus | – | – | – | – | – | 1 (10%)
Centrilobular, hepatocyte, hypertrophy | – | – | – | – | 10 (100%) | 10 (100%)
Hepatocyte, necrosis | – | – | – | – | – | 8 (80%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Salivary glands | (10) | (0) | (0) | (0) | (10) | (10)
Submandibular gland, depletion secretory | – | – | – | – | – | 7 (70%)
Stomach, forestomach | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (10) | (10) | (10) | (10) | (10)
Epithelium, atrophy | – | – | – | – | – | 10 (100%)
Epithelium, hyperplasia | – | – | – | – | – | 10 (100%)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 10 (100%) | – | – | – | – | 4 (40%)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (7) | (0) | (0) | (0) | (0) | (10)
Pituitary gland | (10) | (0) | (0) | (0) | (0) | (10)
Thyroid gland | (10) | (0) | (0) | (0) | (0) | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Epididymis | (10) | (10) | (10) | (10) | (10) | (10)
Exfoliated germ cell | 1 (10%) | 3 (30%) | 1 (10%) | 2 (20%) | 4 (40%) | 10 (100%)
Preputial gland | (10) | (0) | (0) | (0) | (0) | (10)
Prostate | (10) | (0) | (0) | (0) | (0) | (10)
Seminal vesicle | (10) | (0) | (0) | (0) | (0) | (10)
Testes | (10) | (10) | (10) | (10) | (10) | (10)
Elongated spermatid, retention | 5 (50%) | 3 (30%) | – | 1 (10%) | 6 (60%) | 10 (100%)
Germinal epithelium, degeneration | 5 (50%) | 5 (50%) | 3 (30%) | 6 (60%) | 8 (80%) | 10 (100%)
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mandibular | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Thymus | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (1) | (0) | (0) | (0) | (10)
Squamous cell papilloma | – | 1 (100%) | – | – | – | –
Musculoskeletal System
Bone | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic active | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%) | 9 (90%) | 9 (90%)
Metaplasia, osseous | 1 (10%) | – | 1 (10%) | – | – | 1 (10%)
Mineralization | 1 (10%) | – | – | – | – | –
Alveolar epithelium, hyperplasia | – | 1 (10%) | – | – | – | –
Alveolus, infiltration cellular, histiocyte | 9 (90%) | 6 (60%) | 8 (80%) | 9 (90%) | 10 (100%) | 8 (80%)
Pleura, inflammation, chronic | – | – | – | – | – | 1 (10%)
Nose | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic active | – | – | – | – | – | 1 (10%)
Olfactory epithelium, accumulation, hyaline droplet | 2 (20%) | – | – | – | – | 2 (20%)
Olfactory epithelium, degeneration | 1 (10%) | – | – | – | – | –
Olfactory epithelium, metaplasia, squamous | 1 (10%) | – | – | – | – | –
Respiratory epithelium, accumulation, hyaline droplet | 1 (10%) | – | – | – | – | 2 (20%)
Trachea | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | – | – | – | – | – | 1 (10%)
Special Senses System
Eye | (10) | (0) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | 1 (10%) | – | – | – | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Mineralization | 9 (90%) | 7 (70%) | 7 (70%) | 9 (90%) | 10 (100%) | 10 (100%)
Nephropathy | 10 (100%) | 10 (100%) | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%)
Renal tubule, accumulation, hyaline droplet | – | – | – | – | 10 (100%) | 10 (100%)
Renal tubule, dilatation | – | – | – | – | – | 1 (10%)
Urinary bladder | (10) | (0) | (0) | (0) | (0) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths | – | – | – | – | – | –
Moribund | – | – | – | – | – | 1
Natural deaths | – | – | – | – | – | 2
Survivors | – | – | – | – | – | –
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 7
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, duodenum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (0) | (0) | (0) | (0) | (8)
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Fatty change | – | – | – | – | 1 (10%) | 10 (100%)
Hepatodiaphragmatic nodule | 1 (10%) | 3 (30%) | 1 (10%) | 2 (20%) | 1 (10%) | 1 (10%)
Inflammation, granulomatous | 6 (60%) | 6 (60%) | 8 (80%) | 5 (50%) | 10 (100%) | –
Necrosis | – | – | – | – | – | 1 (10%)
Centrilobular, hepatocyte, hypertrophy | – | – | – | – | 10 (100%) | 7 (70%)
Hepatocyte, necrosis | – | – | – | – | – | 6 (60%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Salivary glands | (10) | (0) | (0) | (10) | (10) | (10)
Submandibular gland, depletion secretory | – | – | – | – | 10 (100%) | 7 (70%)
Stomach, forestomach | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, acute | – | – | – | – | – | 1 (10%)
Stomach, glandular | (10) | (10) | (10) | (10) | (10) | (10)
Epithelium, atrophy | – | – | – | – | 5 (50%) | 7 (70%)
Epithelium, hyperplasia | – | – | – | – | – | 7 (70%)
Epithelium, necrosis | – | – | – | – | – | 2 (20%)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 6 (60%) | – | – | – | – | 4 (40%)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (10) | (0) | (0) | (0) | (0) | (8)
Pituitary gland | (10) | (0) | (0) | (0) | (0) | (10)
Thyroid gland | (10) | (0) | (0) | (0) | (0) | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Clitoral gland | (10) | (0) | (0) | (0) | (0) | (10)
Ovary | (10) | (1) | (2) | (1) | (1) | (10)
Cyst | – | 1 (100%) | 2 (100%) | 1 (100%) | 1 (100%) | –
Uterus | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, granulomatous | 2 (20%) | – | – | – | – | –
Lymph node, mandibular | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Thymus | (10) | (0) | (0) | (0) | (0) | (10)
Cortex, depletion lymphoid | – | – | – | – | – | 1 (10%)
Cortex, necrosis, lymphoid | – | – | – | – | – | 3 (30%)
Integumentary System
Mammary gland | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (0) | (0) | (0) | (0) | (10)
Musculoskeletal System
Bone | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Foreign body | – | – | 1 (10%) | – | – | –
Inflammation, chronic active | 2 (20%) | 6 (60%) | 7 (70%) | 7 (70%) | 10 (100%) | 5 (50%)
Mineralization | 1 (10%) | – | – | – | – | –
Alveolus, infiltration cellular, histiocyte | 2 (20%) | 5 (50%) | 8 (80%) | 8 (80%) | 9 (90%) | 7 (70%)
Nose | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation | 1 (10%) | – | – | – | – | –
Inflammation, chronic | 1 (10%) | – | – | – | – | –
Olfactory epithelium, accumulation, hyaline droplet | 6 (60%) | – | – | – | – | 2 (20%)
Respiratory epithelium, accumulation, hyaline droplet | 3 (30%) | – | – | – | – | 2 (20%)
Trachea | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation | 1 (10%) | – | – | – | – | –
Special Senses System
Eye | (10) | (1) | (0) | (0) | (0) | (10)
Hemorrhage | – | 1 (100%) | – | – | – | –
Anterior chamber, exudate | – | – | – | – | – | 1 (10%)
Cornea, inflammation, acute | – | – | – | – | – | 1 (10%)
Posterior chamber, exudate | – | – | – | – | – | 1 (10%)
Retina, degeneration | – | – | – | – | – | 1 (10%)
Harderian gland | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | 1 (10%) | – | – | – | – | –
Acinus, metaplasia | – | – | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Mineralization | 8 (80%) | – | – | – | – | 8 (80%)
Nephropathy | 3 (30%) | – | – | – | – | 2 (20%)
Renal tubule, dilatation | 1 (10%) | – | – | – | – | –
Urinary bladder | (10) | (0) | (0) | (0) | (0) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (0) | (0) | (10)
Gallbladder | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, duodenum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Fatty change | – | – | – | 8 (80%) | 5 (50%) | 10 (100%)
Centrilobular, hepatocyte, hypertrophy | – | – | – | – | 10 (100%) | 10 (100%)
Hepatocyte, necrosis | – | – | – | – | 1 (10%) | 10 (100%)
Hepatocyte, necrosis, focal | 1 (10%) | – | – | – | – | –
Oval cell, hyperplasia | – | – | – | – | – | 10 (100%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Salivary glands | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic | – | – | – | – | 2 (20%) | 4 (40%)
Ulcer | – | – | – | – | – | 2 (20%)
Epithelium, hyperkeratosis | – | – | – | – | 2 (20%) | 3 (30%)
Epithelium, hyperplasia | – | – | – | – | 1 (10%) | 3 (30%)
Epithelium, inflammation, suppurative | – | – | – | – | – | 4 (40%)
Stomach, glandular | (10) | (10) | (10) | (10) | (10) | (10)
Epithelium, atrophy | – | – | – | – | – | 10 (100%)
Epithelium, hyperplasia | – | – | – | – | – | 10 (100%)
Epithelium, necrosis | – | – | – | – | 1 (10%) | –
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Subcapsular, hyperplasia | 2 (20%) | – | – | – | – | 1 (10%)
Adrenal medulla | (10) | (0) | (0) | (0) | (0) | (10)
Islets, pancreatic | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (9) | (0) | (0) | (0) | (0) | (10)
Pituitary gland | (10) | (0) | (0) | (0) | (0) | (10)
Thyroid gland | (10) | (0) | (0) | (0) | (0) | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Epididymis | (10) | (10) | (10) | (10) | (10) | (10)
Preputial gland | (10) | (0) | (0) | (0) | (0) | (10)
Prostate | (10) | (0) | (0) | (0) | (0) | (10)
Seminal vesicle | (10) | (0) | (0) | (0) | (0) | (10)
Testes | (10) | (10) | (10) | (10) | (10) | (10)
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mandibular | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Thymus | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Skin | (10) | (0) | (0) | (0) | (0) | (10)
Musculoskeletal System
Bone | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (0) | (0) | (0) | (1) | (10)
Serosa, inflammation, granulomatous | – | – | – | – | 1 (100%) | –
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Glands, olfactory epithelium, hyperplasia | – | – | – | – | – | 7 (70%)
Nerve, atrophy | – | – | – | – | 8 (80%) | 10 (100%)
Olfactory epithelium, accumulation, hyaline droplet | – | – | – | – | 2 (20%) | 9 (90%)
Olfactory epithelium, atrophy | – | – | – | – | 10 (100%) | 10 (100%)
Respiratory epithelium, accumulation, hyaline droplet | 4 (40%) | 5 (50%) | 1 (10%) | 5 (50%) | 10 (100%) | 10 (100%)
Respiratory epithelium, Vacuolization cytoplasmic | 1 (10%) | 1 (10%) | – | – | – | 6 (60%)
Trachea | (10) | (0) | (0) | (0) | (0) | (10)
Special Senses System
Eye | (10) | (0) | (0) | (0) | (0) | (10)
Retina, atrophy | 1 (10%) | – | – | – | – | –
Harderian gland | (10) | (0) | (0) | (0) | (0) | (10)
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | 1 (10%) | – | – | – | – | –
Nephropathy | 1 (10%) | – | – | – | – | 1 (10%)
Urinary bladder | (10) | (0) | (0) | (0) | (0) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Gavage Study of Myristicin^a^

| Vehicle Control | 10 mg/kg | 30 mg/kg | 100 mg/kg | 300 mg/kg | 600 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (0) | (0) | (10)
Gallbladder | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, duodenum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (9) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Basophilic focus | – | – | 1 (10%) | – | 1 (10%) | –
Clear cell focus | – | – | – | – | 3 (30%) | 2 (20%)
Fatty change | – | – | – | – | – | 10 (100%)
Mineralization, focal | – | – | 1 (10%) | – | – | –
Necrosis | – | – | – | – | 1 (10%) | –
Centrilobular, hepatocyte, hypertrophy | – | – | – | 10 (100%) | 10 (100%) | 10 (100%)
Hepatocyte, necrosis | – | – | – | 1 (10%) | 10 (100%) | 10 (100%)
Oval cell, hyperplasia | – | – | – | – | 10 (100%) | 10 (100%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Salivary glands | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic | – | – | 2 (20%) | 1 (10%) | 1 (10%) | 3 (30%)
Ulcer | – | – | – | 1 (10%) | – | 2 (20%)
Epithelium, hyperkeratosis | – | – | 2 (20%) | 1 (10%) | 1 (10%) | 3 (30%)
Epithelium, hyperplasia | – | – | 2 (20%) | 1 (10%) | 1 (10%) | 3 (30%)
Epithelium, inflammation, suppurative | – | – | 2 (20%) | 1 (10%) | – | 3 (30%)
Stomach, glandular | (10) | (10) | (10) | (10) | (10) | (10)
Epithelium, atrophy | – | – | – | – | – | 10 (100%)
Epithelium, hyperplasia | – | – | – | – | – | 10 (100%)
Epithelium, necrosis | – | – | – | – | 1 (10%) | –
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Subcapsular, hyperplasia | 6 (60%) | – | – | – | – | 5 (50%)
Adrenal medulla | (10) | (0) | (0) | (0) | (0) | (10)
Islets, pancreatic | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (9) | (0) | (0) | (0) | (0) | (9)
Pituitary gland | (10) | (0) | (0) | (0) | (0) | (10)
Thyroid gland | (10) | (0) | (0) | (0) | (0) | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Clitoral gland | (10) | (0) | (0) | (0) | (0) | (10)
Ovary | (10) | (0) | (0) | (0) | (0) | (10)
Uterus | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mandibular | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Thymus | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (0) | (0) | (0) | (0) | (10)
Musculoskeletal System
Bone | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (0) | (0) | (0) | (0) | (10)
Arteriole, inflammation, chronic | 1 (10%) | – | – | – | – | –
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Glands, olfactory epithelium, hyperplasia | – | – | – | – | – | 10 (100%)
Nerve, atrophy | – | – | – | – | 9 (90%) | 10 (100%)
Olfactory epithelium, accumulation, hyaline droplet | – | 1 (10%) | | 3 (30%) | 8 (80%) | 10 (100%)
Olfactory epithelium, atrophy | – | – | – | – | 10 (100%) | 10 (100%)
Respiratory epithelium, accumulation, hyaline droplet | 5 (50%) | 3 (30%) | 1 (10%) | 7 (70%) | 10 (100%) | 10 (100%)
Respiratory epithelium, vacuolization cytoplasmic | – | – | – | – | 2 (20%) | 4 (40%)
Trachea | (10) | (0) | (0) | (0) | (0) | (10)
Special Senses System
Eye | (10) | (0) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (0) | (0) | (0) | (0) | (10)
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Urinary bladder | (10) | (0) | (0) | (0) | (0) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.