# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-94

Report Series: NTP Toxicity Report Series

Report Series Number: 94

Official citation: National Toxicology Program (NTP). 2019. NTP technical report on the toxicity studies of 1020 long multiwalled carbon nanotubes (L-MWNT-1020) administered by inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 94.