# Peer Review

The draft NTP Technical Report on the Toxicity Studies of 1020 Long Multiwalled Carbon Nanotubes(L-MWNT-1020) Administered by Inhalation to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Toxicity Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Tara Sabo-Attwood, Ph.D.
  Department of Environmental and Global Health
  University of Florida
  Gainesville, Florida, USA
- Wanda Haschek-Hock, Ph.D.
  Department of Pathobiology
  University of Illinois
  Urbana, Illinois, USA
- Devon Andres, Ph.D.
  Tauri Group
  Bel Air, Maryland, USA