# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  D.L. Morgan, Ph.D., Study Scientist
  M.F. Cesta, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, Ph.D.
  B. Collins, M.S.
  P.M. Foster, Ph.D.
  D. Germolec, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  G.L. Baker, Ph.D., Study Director
  H.N. Moore, Ph.D., Study Director
  B.K. Hayden
  T.E. Lapainis, Ph.D.
  J. Lovaglio, D.V.M.