# References

1 Tolles WM. Self-assembled materials. Mater Res Soc Bull. 2000; October:36-38. http://dx.doi.org/10.1557/mrs2000.202
2 Donaldson K Aitken R Tran L Stone V Duffin R Forrest G Alexander A Carbon nanotubes: a review of their properties in relation to pulmonary toxicology and workplace safety. Toxicol Sci. 2006;92(1):5–22. http://dx.doi.org/10.1093/toxsci/kfj130 16484287
3 Collins PG Avouris P Nanotubes for electronics. Sci Am. 2000;283(6):62–69. http://dx.doi.org/10.1038/scientificamerican1200-62 11103460
4 Pacurari M Castranova V Vallyathan V Single- and multi-wall carbon nanotubes versus asbestos: are the carbon nanotubes a new health risk to humans? J Toxicol Environ Health A. 2010;73(5):378–395. http://dx.doi.org/10.1080/15287390903486527 20155580
5 Banerjee S Kahn MGC Wong SS Rational chemical strategies for carbon nanotube functionalization. Chemistry. 2003;9(9):1898–1908. http://dx.doi.org/10.1002/chem.200204618 12740836
6 Hou P-X Xu S-T Ying Z Yang Q-H Liu C Cheng H-M Hydrogen adsorption/desorption behavior of multi-walled carbon nanotubes with different diameters. Carbon. 2003;41(13):2471–2476. http://dx.doi.org/10.1016/S0008-6223(03)00271-9
7 Thostenson ET Ren Z Chou T-W Advances in the science and technology of carbon nanotubes and their composites: A review. Compos Sci Technol. 2001;61(13):1899–1912. http://dx.doi.org/10.1016/S0266-3538(01)00094-X
8 De Volder MF Tawfick SH Baughman RH Hart AJ Carbon nanotubes: present and future commercial applications. Science. 2013;339(6119):535–539. 10.1126/science.1222453 23372006
9 Murr LE Guerrero PA Carbon nanotubes in wood soot. Atmos Sci Lett. 2006;7(4):93–95. http://dx.doi.org/10.1002/asl.138
10 Bang JJ Guerrero PA Lopez DA Murr LE Esquivel EV Carbon nanotubes and other fullerene nanocrystals in domestic propane and natural gas combustion streams. J Nanosci Nanotechnol. 2004;4(7):716–718. http://dx.doi.org/10.1166/jnn.2004.095 15570950
11 Research BCC. Global markets and technologies for carbon nanotubes. 2015. Report Code: NAN024F. https://www.bccresearch.com/market-research/nanotechnology/carbon-nantubes-global-markets-technologies-report-nan024f.html [Accessed: July 28, 2016]
12 Eklund P Ajayan P Blackmon R Hart AJ Kong J Pradhan B Rao A Rinzler A WTEC panel report on international assessment of research and development of carbon nanotube manufacturing and applications. Baltimore (MD): World Technology Evaluation Center, Inc; 2007.
13 Chou T-W Gao L Thostenson ET Zhang Z Byun J-H An assessment of the science and technology of carbon nanotube-based fibers and composites. Compos Sci Technol. 2010;70(1):1–19. http://dx.doi.org/10.1016/j.compscitech.2009.10.004
14 Mehra NK Palakurthi S Interactions between carbon nanotubes and bioactives: a drug delivery perspective. Drug Discov Today. 2016;21(4):585–597. http://dx.doi.org/10.1016/j.drudis.2015.11.011 26657088
15 Shim M Shi Kam NW Chen RJ Li Y Dai H Functionalization of carbon nanotubes for biocompatibility and biomolecular recognition. Nano Lett. 2002;2(4):285–288. http://dx.doi.org/10.1021/nl015692j
16 Pantarotto D Briand J-P Prato M Bianco A Translocation of bioactive peptides across cell membranes by carbon nanotubes. Chem Commun (Camb). 2004;(1):16–17. http://dx.doi.org/10.1039/b311254c 14737310
17 Shi Kam NW Jessop TC Wender PA Dai H Nanotube molecular transporters: internalization of carbon nanotube-protein conjugates into Mammalian cells. J Am Chem Soc. 2004;126(22):6850–6851. http://dx.doi.org/10.1021/ja0486059 15174838
18 Bianco A Kostarelos K Partidos CD Prato M Biomedical applications of functionalised carbon nanotubes. Chem Commun (Camb). 2005;(5):571–577. http://dx.doi.org/10.1039/b410943k 15672140
19 Zharov VP, Kim J-W, Curiel DT, Everts M. Self-assembling nanoclusters in living systems: Application for integrated photothermal nanodiagnostics and nanotherapy. Nanomed Nanotechnol Biol Med. 2005; 1(4):326-345. http://dx.doi.org/10.1016/j.nano.2005.10.006
20 Liu Z Winters M Holodniy M Dai H siRNA delivery into human T cells and primary cells with carbon-nanotube transporters. Angew Chem Int Ed Engl. 2007;46(12):2023–2027. http://dx.doi.org/10.1002/anie.200604295 17290476
21 Lalwani G Henslee AM Farshid B Lin L Kasper FK Qin Y-X Mikos AG Sitharaman B Two-dimensional nanostructure-reinforced biodegradable polymeric nanocomposites for bone tissue engineering. Biomacromolecules. 2013;14(3):900–909. http://dx.doi.org/10.1021/bm301995s 23405887
22 Bello D Hart AJ Ahn K Hallock M Yamamoto N Garcia EJ Ellenbecker MJ Wardle BL Particle exposure levels during CVD growth and subsequent handling of vertically-aligned carbon nanotube films. Carbon. 2008;46(6):974–977. http://dx.doi.org/10.1016/j.carbon.2008.03.003
23 Bello D Wardle BL Yamamoto N Guzman deVilloria R Garcia EJ Hart AJ Ahn K Ellenbecker MJ Hallock M Exposure to nanoscale particles and fibers during machining of hybrid advanced composites containing carbon nanotubes. J Nanopart Res. 2009;11(1):231–249. http://dx.doi.org/10.1007/s11051-008-9499-4
24 Bello D Wardle BL Zhang J Yamamoto N Santeufemio C Hallock M Virji MA Characterization of exposures to nanoscale particles and fibers during solid core drilling of hybrid carbon nanotube advanced composites. Int J Occup Environ Health. 2010;16(4):434–450. http://dx.doi.org/10.1179/oeh.2010.16.4.434 21222387
25 Han JH Lee EJ Lee JH So KP Lee YH Bae GN Lee S-B Ji JH Cho MH Yu IJ Monitoring multiwalled carbon nanotube exposure in carbon nanotube research facility. Inhal Toxicol. 2008;20(8):741–749. http://dx.doi.org/10.1080/08958370801942238 18569096
26 Tsai S-J Hofmann M Hallock M Ada E Kong J Ellenbecker M Characterization and evaluation of nanoparticle release during the synthesis of single-walled and multiwalled carbon nanotubes by chemical vapor deposition. Environ Sci Technol. 2009;43(15):6017–6023. http://dx.doi.org/10.1021/es900486y 19731712
27 Lee JH Lee S-B Bae GN Jeon KS Yoon JU Ji JH Sung JH Lee BG Lee JH Yang JS Exposure assessment of carbon nanotube manufacturing workplaces. Inhal Toxicol. 2010;22(5):369–381. http://dx.doi.org/10.3109/08958370903367359 20121582
28 Methner M Hodson L Dames A Geraci C Nanoparticle Emission Assessment Technique (NEAT) for the identification and measurement of potential inhalation exposure to engineered nanomaterials—Part B: results from 12 field studies. J Occup Environ Hyg. 2010;7(3):163–176. http://dx.doi.org/10.1080/15459620903508066 20063229
29 Cena LG Peters TM Characterization and control of airborne particles emitted during production of epoxy/carbon nanotube nanocomposites. J Occup Environ Hyg. 2011;8(2):86–92. http://dx.doi.org/10.1080/15459624.2011.545943 21253981
30 Dahm MM Evans DE Schubauer-Berigan MK Birch ME Fernback JE Occupational exposure assessment in carbon nanotube and nanofiber primary and secondary manufacturers. Ann Occup Hyg. 2012;56(5):542–556. 22156567
31 Kuijpers E Bekker C Fransman W Brouwer D Tromp P Vlaanderen J Godderis L Hoet P Lan Q Silverman D Occupational exposure to multi-walled carbon nanotubes during commercial production synthesis and handling. Ann Occup Hyg. 2016;60(3):305–317. http://dx.doi.org/10.1093/annhyg/mev082 26613611
32 Johnson DR Methner MM Kennedy AJ Steevens JA Potential for occupational exposure to engineered carbon-based nanomaterials in environmental laboratory studies. Environ Health Perspect. 2010;118(1):49–54. http://dx.doi.org/10.1289/ehp.0901076 20056572
33 Guseva Canu I Bateson TF Bouvard V Debia M Dion C Savolainen K Yu I-J Human exposure to carbon-based fibrous nanomaterials: A review. Int J Hyg Environ Health. 2016;219(2):166–175. http://dx.doi.org/10.1016/j.ijheh.2015.12.005 26752069
34 Maynard AD Kuempel ED Airborne nanostructured particles and occupational health. J Nanopart Res. 2005;7(6):587–614. http://dx.doi.org/10.1007/s11051-005-6770-9
35 Occupational Safety and Health Administration (OSHA). OSHA fact sheet 3634: Working safely with nanomaterials. Washington, DC: U.S. Department of Labor, OSHA; 2013. https://www.osha.gov/publications/OSHA_FS-3634.pdf [Accessed June 27, 2016]
36 National Institute for Occupational Safety and Health (NIOSH). Current intelligence bulletin 65: Occupational exposure to carbon nanotubes and nanofibers. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, NIOSH; 2013. DHHS (NIOSH) Publication No. 2013-145.
37 Osier M Oberdörster G Intratracheal inhalation vs intratracheal instillation: differences in particle effects. Fundam Appl Toxicol. 1997;40(2):220–227. http://dx.doi.org/10.1006/faat.1997.2390 9441718
38 Warheit DB Laurence BR Reed KL Roach DH Reynolds GAM Webb TR Comparative pulmonary toxicity assessment of single-wall carbon nanotubes in rats. Toxicol Sci. 2004;77(1):117–125. http://dx.doi.org/10.1093/toxsci/kfg228 14514968
39 Morrow PE Haseman JK Hobbs CH Driscoll KE Vu V Oberdörster G The maximum tolerated dose for inhalation bioassays: toxicity vs overload. Fundam Appl Toxicol. 1996;29(2):155–167. http://dx.doi.org/10.1006/faat.1996.0017 8742311
40 Ryman-Rasmussen JP Cesta MF Brody AR Shipley-Phillips JK Everitt JI Tewksbury EW Moss OR Wong BA Dodd DE Andersen ME Inhaled carbon nanotubes reach the subpleural tissue in mice. Nat Nanotechnol. 2009;4(11):747–751. http://dx.doi.org/10.1038/nnano.2009.305 19893520
41 Mercer RR Scabilloni JF Hubbs AF Battelli LA McKinney W Friend S Wolfarth MG Andrew M Castranova V Porter DW Distribution and fibrotic response following inhalation exposure to multi-walled carbon nanotubes. Part Fibre Toxicol. 2013;10(1):33. http://dx.doi.org/10.1186/1743-8977-10-33 23895460
42 Porter DW Hubbs AF Chen BT McKinney W Mercer RR Wolfarth MG Battelli L Wu N Sriram K Leonard S Acute pulmonary dose-responses to inhaled multi-walled carbon nanotubes. Nanotoxicology. 2013;7(7):1179–1194. http://dx.doi.org/10.3109/17435390.2012.719649 22881873
43 Lippmann M Asbestos exposure indices. Environ Res. 1988;46(1):86–106. http://dx.doi.org/10.1016/S0013-9351(88)80061-6 3286241
44 Lippmann M Effects of fiber characteristics on lung deposition, retention, and disease. Environ Health Perspect. 1990;88:311–317. http://dx.doi.org/10.1289/ehp.9088311 2272328
45 Sanchez VC Weston P Yan A Hurt RH Kane AB A 3-dimensional in vitro model of epithelioid granulomas induced by high aspect ratio nanomaterials. Part Fibre Toxicol. 2011;8(1):17. http://dx.doi.org/10.1186/1743-8977-8-17 21592387
46 Murphy FA Schinwald A Poland CA Donaldson K The mechanism of pleural inflammation by long carbon nanotubes: interaction of long fibres with macrophages stimulates them to amplify pro-inflammatory responses in mesothelial cells. Part Fibre Toxicol. 2012;9(1):8. http://dx.doi.org/10.1186/1743-8977-9-8 22472194
47 Morrow PE Dust overloading of the lungs: update and appraisal. Toxicol Appl Pharmacol. 1992;113(1):1–12. http://dx.doi.org/10.1016/0041-008X(92)90002-A 1553742
48 Oberdörster G Ferin J Morrow PE Volumetric loading of alveolar macrophages (AM): a possible basis for diminished AM-mediated particle clearance. Exp Lung Res. 1992;18(1):87–104. http://dx.doi.org/10.3109/01902149209020653 1572327
49 Pauluhn J Subchronic 13-week inhalation exposure of rats to multiwalled carbon nanotubes: toxic effects are determined by density of agglomerate structures, not fibrillar structures. Toxicol Sci. 2010;113(1):226–242. http://dx.doi.org/10.1093/toxsci/kfp247 19822600
50 Sturm R A stochastic model of carbon nanotube deposition in the airways and alveoli of the human respiratory tract. Inhal Toxicol. 2016;28(2):49–60. http://dx.doi.org/10.3109/08958378.2015.1136009 26895306
51 Mitchell LA Gao J Wal RV Gigliotti A Burchiel SW McDonald JD Pulmonary and systemic immune response to inhaled multiwalled carbon nanotubes. Toxicol Sci. 2007;100(1):203–214. http://dx.doi.org/10.1093/toxsci/kfm196 17660506
52 Ma-Hock L Treumann S Strauss V Brill S Luizi F Mertler M Wiench K Gamer AO van Ravenzwaay B Landsiedel R Inhalation toxicity of multiwall carbon nanotubes in rats exposed for 3 months. Toxicol Sci. 2009;112(2):468–481. http://dx.doi.org/10.1093/toxsci/kfp146 19584127
53 Ellinger-Ziegelbauer H Pauluhn J Pulmonary toxicity of multi-walled carbon nanotubes (Baytubes) relative to α-quartz following a single 6h inhalation exposure of rats and a 3 months post-exposure period. Toxicology. 2009;266(1-3):16–29. http://dx.doi.org/10.1016/j.tox.2009.10.007 19836432
54 Pauluhn J. Comparative pulmonary response to inhaled nanostructures: Considerations on test design and endpoints. Inhal Toxicol. 2009; 21(sup1):40-54.
55 Pothmann D Simar S Schuler D Dony E Gaering S Le Net J-L Okazaki Y Chabagno JM Bessibes C Beausoleil J Lung inflammation and lack of genotoxicity in the comet and micronucleus assays of industrial multiwalled carbon nanotubes Graphistrength(©) C100 after a 90-day nose-only inhalation exposure of rats. Part Fibre Toxicol. 2015;12(1):21. http://dx.doi.org/10.1186/s12989-015-0096-2 26156627
56 Kasai T Umeda Y Ohnishi M Kondo H Takeuchi T Aiso S Nishizawa T Matsumoto M Fukushima S Thirteen-week study of toxicity of fiber-like multi-walled carbon nanotubes with whole-body inhalation exposure in rats. Nanotoxicology. 2015;9(4):413–422. http://dx.doi.org/10.3109/17435390.2014.933903 25030099
57 Shvedova AA Kisin ER Mercer R Murray AR Johnson VJ Potapovich AI Tyurina YY Gorelik O Arepalli S Schwegler-Berry D Unusual inflammatory and fibrogenic pulmonary responses to single-walled carbon nanotubes in mice. Am J Physiol Lung Cell Mol Physiol. 2005;289(5):L698–L708. http://dx.doi.org/10.1152/ajplung.00084.2005 15951334
58 Madl AK Pinkerton KE Health effects of inhaled engineered and incidental nanoparticles. Crit Rev Toxicol. 2009;39(8):629–658. http://dx.doi.org/10.1080/10408440903133788 19743943
59 Baisch BL Corson NM Wade-Mercer P Gelein R Kennell AJ Oberdörster G Elder A Equivalent titanium dioxide nanoparticle deposition by intratracheal instillation and whole body inhalation: the effect of dose rate on acute respiratory tract inflammation. Part Fibre Toxicol. 2014;11(1):5. http://dx.doi.org/10.1186/1743-8977-11-5 24456852
60 Silva RM Doudrick K Franzi LM TeeSy C Anderson DS Wu Z Mitra S Vu V Dutrow G Evans JE Instillation versus inhalation of multiwalled carbon nanotubes: exposure-related health effects, clearance, and the role of particle characteristics. ACS Nano. 2014;8(9):8911–8931. http://dx.doi.org/10.1021/nn503887r 25144856
61 Landsiedel R Sauer UG Ma-Hock L Schnekenburger J Wiemann M Pulmonary toxicity of nanomaterials: a critical comparison of published in vitro assays and in vivo inhalation or instillation studies. Nanomedicine (Lond). 2014;9(16):2557–2585. http://dx.doi.org/10.2217/nnm.14.149 25490426
62 Fatkhutdinova LM Khaliullin TO Vasil’yeva OL Zalyalov RR Mustafin IG Kisin ER Birch ME Yanamala N Shvedova AA Fibrosis biomarkers in workers exposed to MWCNTs. Toxicol Appl Pharmacol. 2016;299:125–131. http://dx.doi.org/10.1016/j.taap.2016.02.016 26902652
63 Shvedova AA Yanamala N Kisin ER Khailullin TO Birch ME Fatkhutdinova LM Integrated analysis of dysregulated ncRNA and mRNA expression profiles in humans exposed to carbon nanotubes. PLoS One. 2016;11(3):e0150628. http://dx.doi.org/10.1371/journal.pone.0150628 26930275
64 Lee JS Choi YC Shin JH Lee JH Lee Y Park SY Baek JE Park JD Ahn K Yu IJ Health surveillance study of workers who manufacture multi-walled carbon nanotubes. Nanotoxicology. 2015;9(6):802–811. http://dx.doi.org/10.3109/17435390.2014.978404 25395166
65 Kasai T Umeda Y Ohnishi M Mine T Kondo H Takeuchi T Matsumoto M Fukushima S Lung carcinogenicity of inhaled multi-walled carbon nanotube in rats. Part Fibre Toxicol. 2016;13(1):53. http://dx.doi.org/10.1186/s12989-016-0164-2 27737701
66 Sargent LM Porter DW Staska LM Hubbs AF Lowry DT Battelli L Siegrist KJ Kashon ML Mercer RR Bauer AK Promotion of lung adenocarcinoma following inhalation exposure to multi-walled carbon nanotubes. Part Fibre Toxicol. 2014;11(1):3. http://dx.doi.org/10.1186/1743-8977-11-3 24405760
67 Grosse Y Loomis D Guyton KZ Lauby-Secretan B El Ghissassi F Bouvard V Benbrahim-Tallaa L Guha N Scoccianti C Mattock HInternational Agency for Research on Cancer Monograph Working Group Carcinogenicity of fluoro-edenite, silicon carbide fibres and whiskers, and carbon nanotubes. Lancet Oncol. 2014;15(13):1427–1428. http://dx.doi.org/10.1016/S1470-2045(14)71109-X 25499275
68 Sakamoto Y Nakae D Fukumori N Tayama K Maekawa A Imai K Hirose A Nishimura T Ohashi N Ogata A Induction of mesothelioma by a single intrascrotal administration of multi-wall carbon nanotube in intact male Fischer 344 rats. J Toxicol Sci. 2009;34(1):65–76. http://dx.doi.org/10.2131/jts.34.65 19182436
69 Takagi A Hirose A Nishimura T Fukumori N Ogata A Ohashi N Kitajima S Kanno J Induction of mesothelioma in p53+/- mouse by intraperitoneal application of multi-wall carbon nanotube. J Toxicol Sci. 2008;33(1):105–116. http://dx.doi.org/10.2131/jts.33.105 18303189
70 Takagi A Hirose A Futakuchi M Tsuda H Kanno J Dose-dependent mesothelioma induction by intraperitoneal administration of multi-wall carbon nanotubes in p53 heterozygous mice. Cancer Sci. 2012;103(8):1440–1444. http://dx.doi.org/10.1111/j.1349-7006.2012.02318.x 22537085
71 Nagai H Okazaki Y Chew SH Misawa N Yamashita Y Akatsuka S Ishihara T Yamashita K Yoshikawa Y Yasui H Diameter and rigidity of multiwalled carbon nanotubes are critical factors in mesothelial injury and carcinogenesis. Proc Natl Acad Sci USA. 2011;108(49):E1330–E1338. http://dx.doi.org/10.1073/pnas.1110013108 22084097
72 Rittinghausen S Hackbarth A Creutzenberg O Ernst H Heinrich U Leonhardt A Schaudien D The carcinogenic effect of various multi-walled carbon nanotubes (MWCNTs) after intraperitoneal injection in rats. Part Fibre Toxicol. 2014;11(1):59. http://dx.doi.org/10.1186/s12989-014-0059-z 25410479
73 International Agency for Research on Cancer (IARC) IARC monographs on the evaluation of the carcinogenic risks to humans: Some nanomaterials and some fibres. Vol. 111. Lyon, France: IARC; 2017.
74 Magdolenova Z Collins A Kumar A Dhawan A Stone V Dusinska M Mechanisms of genotoxicity. A review of in vitro and in vivo studies with engineered nanoparticles. Nanotoxicology. 2014;8(3):233–278. http://dx.doi.org/10.3109/17435390.2013.773464 23379603
75 Kuempel ED Jaurand M-C Møller P Morimoto Y Kobayashi N Pinkerton KE Sargent LM Vermeulen RCH Fubini B Kane AB Evaluating the mechanistic evidence and key data gaps in assessing the potential carcinogenicity of carbon nanotubes and nanofibers in humans. Crit Rev Toxicol. 2017;47(1):1–58. http://dx.doi.org/10.1080/10408444.2016.1206061 27537422
76 Møller P Jacobsen NR Weight of evidence analysis for assessing the genotoxic potential of carbon nanotubes. Crit Rev Toxicol. 2017;47(10):867–884. http://dx.doi.org/10.1080/10408444.2017.1367755 28937307
77 Kim JS Sung JH Song KS Lee JH Kim SM Lee GH Ahn KH Lee JS Shin JH Park JD Persistent DNA damage measured by comet assay of Sprague Dawley rat lung cells after five days of inhalation exposure and 1 month post-exposure to dispersed multi-wall carbon nanotubes (MWCNTs) generated by new MWCNT aerosol generation system. Toxicol Sci. 2012;128(2):439–448. http://dx.doi.org/10.1093/toxsci/kfs161 22543278
78 Kim JS Sung JH Choi BG Ryu HY Song KS Shin JH Lee JS Hwang JH Lee JH Lee GH In vivo genotoxicity evaluation of lung cells from Fischer 344 rats following 28 days of inhalation exposure to MWCNTs, plus 28 days and 90 days post-exposure. Inhal Toxicol. 2014;26(4):222–234. http://dx.doi.org/10.3109/08958378.2013.878006 24568578
79 Visalli G Bertuccio MP Iannazzo D Piperno A Pistone A Di Pietro A Toxicological assessment of multi-walled carbon nanotubes on A549 human lung epithelial cells. Toxicol In Vitro. 2015;29(2):352–362. http://dx.doi.org/10.1016/j.tiv.2014.12.004 25499066
80 Muller J Huaux F Moreau N Misson P Heilier J-F Delos M Arras M Fonseca A Nagy JB Lison D Respiratory toxicity of multi-wall carbon nanotubes. Toxicol Appl Pharmacol. 2005;207(3):221–231. http://dx.doi.org/10.1016/j.taap.2005.01.008 16129115
81 Smart SK Cassady AI Lu GQ Martin DJ The biocompatibility of carbon nanotubes. Carbon. 2006;44(6):1034–1047. http://dx.doi.org/10.1016/j.carbon.2005.10.011
82 Levine KE, Han L, McWilliams AC, Essader AS, Amato KE, Fernando RA, Browning DB, Greene LC, Ensor DS, Walker NJ. Characterization of an assortment of commercially available multiwalled carbon nanotubes. Microchimica Acta. 2014; 181(1-2):171-179. http://dx.doi.org/10.1007/s00604-013-1088-2
83 Datsyuk V Kalyva M Papagelis K Parthenios J Tasis D Siokou A Kallitsis I Galiotis C Chemical oxidation of multiwalled carbon nanotubes. Carbon. 2008;46(6):833–840. http://dx.doi.org/10.1016/j.carbon.2008.02.012
84 Stobinski L Lesiak B Kövér L Tóth J Biniak S Trykowski G Judek J Multiwall carbon nanotubes purification and oxidation by nitric acid studied by the FTIR and electron spectroscopy methods. J Alloys Compd. 2010;501(1):77–84. http://dx.doi.org/10.1016/j.jallcom.2010.04.032
85 Vaisman L Marom G Wagner HD Dispersions of surface‐modified carbon nanotubes in water‐soluble and water‐insoluble polymers. Adv Funct Mater. 2006;16(3):357–363. http://dx.doi.org/10.1002/adfm.200500142
86 Hill MA, Watson CR, Moss OR. NEWCAS: An interactive computer program for particle size analysis. Richland, WA: Pacific Northwest Laboratory; 1977. PNL-2405, UC-32.
87 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
88 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyer Publications; 1985. p. 345–357.
89 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
90 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. http://dx.doi.org/10.1080/01621459.1955.10501294
91 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971:103-117. http://dx.doi.org/10.2307/2528930
92 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972:519-531. http://dx.doi.org/10.2307/2556164
93 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
94 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986:183-186. http://dx.doi.org/10.2307/2531254
95 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252. http://dx.doi.org/10.1080/00401706.1964.10490181
96 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1/2):133–145. http://dx.doi.org/10.2307/2333011
97 Dixon WJ Massey FJ Jr Introduction to statistical analysis. 2nd ed. New York (NY): McGraw-Hill Book Company, Inc; 1957. p. 276–278, 412.
98 Code of Federal Regulations (CFR). 21:Part 58.
99 Snyder-Talkington BN Dong C Porter DW Ducatman B Wolfarth MG Andrew M Battelli L Raese R Castranova V Guo NL Multiwalled carbon nanotube-induced pulmonary inflammatory and fibrotic responses and genomic changes following aspiration exposure in mice: A 1-year postexposure study. J Toxicol Environ Health A. 2016;79(8):352–366. http://dx.doi.org/10.1080/15287394.2016.1159635 27092743
100 International Agency for Research on Cancer (IARC) IARC monographs on the evaluation of the carcinogenic risks to humans: Arsenic, metals, fibres, and dusts. Vol 100c. Lyon, France: IARC; 2012.
101 Donaldson K, Poland CA, Murphy FA, MacFarlane M, Chernova T, Schinwald A. Pulmonary toxicity of carbon nanotubes and asbestos—similarities and differences. Adv Drug Del Rev. 2013; 65(15):2078-2086. http://dx.doi.org/10.1016/j.addr.2013.07.014
102 Hubbs AF Mercer RR Benkovic SA Harkema J Sriram K Schwegler-Berry D Goravanahally MP Nurkiewicz TR Castranova V Sargent LM Nanotoxicology—a pathologist’s perspective. Toxicol Pathol. 2011;39(2):301–324. http://dx.doi.org/10.1177/0192623310390705 21422259
103 Ji JH Jung JH Kim SS Yoon J-U Park JD Choi BS Chung YH Kwon IH Jeong J Han BS Twenty-eight-day inhalation toxicity study of silver nanoparticles in Sprague-Dawley rats. Inhal Toxicol. 2007;19(10):857–871. http://dx.doi.org/10.1080/08958370701432108 17687717
104 Warheit DB Webb TR Reed KL Frerichs S Sayes CM Pulmonary toxicity study in rats with three forms of ultrafine-TiO2 particles: differential responses related to surface properties. Toxicology. 2007;230(1):90–104. http://dx.doi.org/10.1016/j.tox.2006.11.002 17196727
105 Warheit DB Webb TR Colvin VL Reed KL Sayes CM Pulmonary bioassay studies with nanoscale and fine-quartz particles in rats: toxicity is not dependent upon particle size but on surface characteristics. Toxicol Sci. 2007;95(1):270–280. http://dx.doi.org/10.1093/toxsci/kfl128 17030555
106 Yang W Peters JI Williams RO 3rd Inhaled nanoparticles—a current review. Int J Pharm. 2008;356(1-2):239–247. http://dx.doi.org/10.1016/j.ijpharm.2008.02.011 18358652
107 Pauluhn J Poorly soluble particulates: searching for a unifying denominator of nanoparticles and fine particles for DNEL estimation. Toxicology. 2011;279(1-3):176–188. http://dx.doi.org/10.1016/j.tox.2010.10.009 21074595
108 Sung JH Ji JH Park JD Yoon JU Kim DS Jeon KS Song MY Jeong J Han BS Han JH Subchronic inhalation toxicity of silver nanoparticles. Toxicol Sci. 2009;108(2):452–461. http://dx.doi.org/10.1093/toxsci/kfn246 19033393
109 Braakhuis HM Park MVDZ Gosens I De Jong WH Cassee FR Physicochemical characteristics of nanomaterials that affect pulmonary inflammation. Part Fibre Toxicol. 2014;11(1):18. http://dx.doi.org/10.1186/1743-8977-11-18 24725891
110 Meunier E, Coste A, Olagnier D, Authier H, Lefèvre L, Dardenne C, Bernad J, Béraud M, Flahaut E, Pipy B. Double-walled carbon nanotubes trigger IL-1β release in human monocytes through Nlrp3 inflammasome activation. Nanomed Nanotechnol Biol Med. 2012; 8(6):987-995. http://dx.doi.org/10.1016/j.nano.2011.11.004
111 Pulskamp K Diabaté S Krug HF Carbon nanotubes show no sign of acute toxicity but induce intracellular reactive oxygen species in dependence on contaminants. Toxicol Lett. 2007;168(1):58–74. http://dx.doi.org/10.1016/j.toxlet.2006.11.001 17141434
112 Ye S Wang Y Jiao F Zhang H Lin C Wu Y Zhang Q The role of NADPH oxidase in multi-walled carbon nanotubes-induced oxidative stress and cytotoxicity in human macrophages. J Nanosci Nanotechnol. 2011;11(5):3773–3781. http://dx.doi.org/10.1166/jnn.2011.3862 21780368
113 Inoue K Takano H Koike E Yanagisawa R Sakurai M Tasaka S Ishizaka A Shimada A Effects of pulmonary exposure to carbon nanotubes on lung and systemic inflammation with coagulatory disturbance induced by lipopolysaccharide in mice. Exp Biol Med (Maywood). 2008;233(12):1583–1590. http://dx.doi.org/10.3181/0805-RM-179 18849540
114 Crouzier D Follot S Gentilhomme E Flahaut E Arnaud R Dabouis V Castellarin C Debouzy J-C Carbon nanotubes induce inflammation but decrease the production of reactive oxygen species in lung. Toxicology. 2010;272(1-3):39–45. http://dx.doi.org/10.1016/j.tox.2010.04.001 20381574
115 Shvedova AA Pietroiusti A Fadeel B Kagan VE Mechanisms of carbon nanotube-induced toxicity: focus on oxidative stress. Toxicol Appl Pharmacol. 2012;261(2):121–133. http://dx.doi.org/10.1016/j.taap.2012.03.023 22513272
116 Dong J Ma Q Suppression of basal and carbon nanotube-induced oxidative stress, inflammation and fibrosis in mouse lungs by Nrf2. Nanotoxicology. 2016;10(6):699–709. http://dx.doi.org/10.3109/17435390.2015.1110758 26592091
117 Gaté L Knudsen KB Seidel C Berthing T Chézeau L Jacobsen NR Valentino S Wallin H Bau S Wolff H Pulmonary toxicity of two different multi-walled carbon nanotubes in rat: comparison between intratracheal instillation and inhalation exposure. Toxicol Appl Pharmacol. 2019;375:17–31. http://dx.doi.org/10.1016/j.taap.2019.05.001 31075343
118 El-Gazzar AM Abdelgied M Alexander DB Alexander WT Numano T Iigo M Naiki A Takahashi S Takase H Hirose A Comparative pulmonary toxicity of a DWCNT and MWCNT-7 in rats. Arch Toxicol. 2019;93(1):49–59. http://dx.doi.org/10.1007/s00204-018-2336-3 30341734
119 Bhattacharya K, Mukherjee SP, Gallud A, Burkert SC, Bistarelli S, Bellucci S, Bottini M, Star A, Fadeel B. Biological interactions of carbon-based nanomaterials: From coronation to degradation. Nanomed Nanotechnol Biol Med. 2016; 12(2):333-351. http://dx.doi.org/10.1016/j.nano.2015.11.011
120 Sayan M Mossman BT The NLRP3 inflammasome in pathogenic particle and fibre-associated lung inflammation and diseases. Part Fibre Toxicol. 2016;13(1):51. http://dx.doi.org/10.1186/s12989-016-0162-4 27650313
121 Jessop F Hamilton RF Jr Rhoderick JF Fletcher P Holian A Phagolysosome acidification is required for silica and engineered nanoparticle-induced lysosome membrane permeabilization and resultant NLRP3 inflammasome activity. Toxicol Appl Pharmacol. 2017;318:58–68. http://dx.doi.org/10.1016/j.taap.2017.01.012 28126413
122 Knudsen KB Berthing T Jackson P Poulsen SS Mortensen A Jacobsen NR Skaug V Szarek J Hougaard KS Wolff H Physicochemical predictors of Multi-Walled Carbon Nanotube-induced pulmonary histopathology and toxicity one year after pulmonary deposition of 11 different Multi-Walled Carbon Nanotubes in mice. Basic Clin Pharmacol Toxicol. 2019;124(2):211–227. http://dx.doi.org/10.1111/bcpt.13119 30168672
123 Cesta MF, Herbert RA, Brix A, Malarkey DE, Sills RC. Lung, epithelium, alveolus – hyperplasia In: National Toxicology Program Nonneoplastic Lesion Atlas. U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2015. https://ntp.niehs.nih.gov/nnl/respiratory/lung/epivhyp [Accessed: April 4, 2018]
124 Owen K Regulatory toxicology considerations for the development of inhaled pharmaceuticals. Drug Chem Toxicol. 2013;36(1):109–118. http://dx.doi.org/10.3109/01480545.2011.648327 22273711
125 Buckley LA Morgan KT Swenberg JA James RA Hamm TE Jr Barrow CS The toxicity of dimethylamine in F-344 rats and B6C3F1 mice following a 1-year inhalation exposure. Fundam Appl Toxicol. 1985;5(2):341–352. http://dx.doi.org/10.1016/0272-0590(85)90082-X 3988003
126 Gopinath C Prentice DE Lewis DJ Atlas of Experimental Toxicological Pathology. Netherlands: Springer; 1987. The respiratory system; p. 22–42.http://dx.doi.org/10.1007/978-94-009-3189-3_3
127 Lewis DJ Morphological assessment of pathological changes within the rat larynx. Toxicol Pathol. 1991;19(4 Pt 1):352–357. http://dx.doi.org/10.1177/0192623391019004-104 1813981
128 Miller RA Renne RA Effects of xenobiotics on the larynx of the rat, mouse, and hamster. In: Jones TC Dungworth DL Mohr Ueditors. Respiratory System. 2nd ed. Berlin, Germany: Springer-Verlag; 1996. p. 51–57.http://dx.doi.org/10.1007/978-3-642-61042-4_5
129 Kaufmann W Bader R Ernst H Harada T Hardisty J Kittel B Kolling A Pino M Renne R Rittinghausen S 1st international ESTP expert workshop: “Larynx squamous metaplasia”. A re-consideration of morphology and diagnostic approaches in rodent studies and its relevance for human risk assessment. Exp Toxicol Pathol. 2009;61(6):591–603. http://dx.doi.org/10.1016/j.etp.2009.01.001 19285845
130 Renne RA Gideon KM Types and patterns of response in the larynx following inhalation. Toxicol Pathol. 2006;34(3):281–285. http://dx.doi.org/10.1080/01926230600695631 16698727
131 Renne RA Gideon KM Harbo SJ Staska LM Grumbein SL Upper respiratory tract lesions in inhalation toxicology. Toxicol Pathol. 2007;35(1):163–169. http://dx.doi.org/10.1080/01926230601052667 17325985
132 Burger GT Renne RA Sagartz JW Ayres PH Coggins CRE Mosberg AT Hayes AW Histologic changes in the respiratory tract induced by inhalation of xenobiotics: physiologic adaptation or toxicity? Toxicol Appl Pharmacol. 1989;101(3):521–542. http://dx.doi.org/10.1016/0041-008X(89)90200-7 2690398
133 Takahashi H Sano H Chiba H Kuroki Y Pulmonary surfactant proteins A and D: innate immune functions and biomarkers for lung diseases. Curr Pharm Des. 2006;12(5):589–598. http://dx.doi.org/10.2174/138161206775474387 16472150
134 Kitamura T Tanaka N Watanabe J Uchida Kanegasaki S Yamada Y Nakata K Idiopathic pulmonary alveolar proteinosis as an autoimmune disease with neutralizing antibody against granulocyte/macrophage colony-stimulating factor. J Exp Med. 1999;190(6):875–880. http://dx.doi.org/10.1084/jem.190.6.875 10499925
135 Martinez-Moczygemba M Doan ML Elidemir O Fan LL Cheung SW Lei JT Moore JP Tavana G Lewis LR Zhu Y Pulmonary alveolar proteinosis caused by deletion of the GM-CSFRalpha gene in the X chromosome pseudoautosomal region 1. J Exp Med. 2008;205(12):2711–2716. http://dx.doi.org/10.1084/jem.20080759 18955567
136 Suzuki T Sakagami T Rubin BK Nogee LM Wood RE Zimmerman SL Smolarek T Dishop MK Wert SE Whitsett JA Familial pulmonary alveolar proteinosis caused by mutations in CSF2RA. J Exp Med. 2008;205(12):2703–2710. http://dx.doi.org/10.1084/jem.20080990 18955570
137 Carey B Trapnell BC The molecular basis of pulmonary alveolar proteinosis. Clin Immunol. 2010;135(2):223–235. http://dx.doi.org/10.1016/j.clim.2010.02.017 20338813
138 Rosen SH Castleman B Liebow AA Enzinger FM Hunt RTN Pulmonary alveolar proteinosis. N Engl J Med. 1958;258(23):1123–1142. http://dx.doi.org/10.1056/NEJM195806052582301 13552931
139 Davidson JM Macleod WM Pulmonary alveolar proteinosis. Br J Dis Chest. 1969;63(1):13–28. 10.1016/S0007-0971(69)80040-9 4886263
140 Xipell JM Ham KN Price CG Thomas DP Acute silicoproteinosis. Thorax. 1977;32(1):104–111. http://dx.doi.org/10.1136/thx.32.1.104 190727
141 Miller RR Churg AM Hutcheon M Lom S Pulmonary alveolar proteinosis and aluminum dust exposure. Am Rev Respir Dis. 1984;130(2):312–315. http://dx.doi.org/10.1164/arrd.1984.130.2.312 6465685
142 McCunney RJ Godefroi R Pulmonary alveolar proteinosis and cement dust: a case report. J Occup Med. 1989;31(3):233–237. http://dx.doi.org/10.1097/00043764-198903000-00008 2918407
143 Dawkins SA Gerhard H Nevin M Pulmonary alveolar proteinosis: a possible sequel of NO2 exposure. J Occup Med. 1991;33(5):638–641. http://dx.doi.org/10.1097/00007611-199109001-00015 1870017
144 Keller CA Frost A Cagle PT Abraham JL Pulmonary alveolar proteinosis in a painter with elevated pulmonary concentrations of titanium. Chest. 1995;108(1):277–280. http://dx.doi.org/10.1378/chest.108.1.277 7606971
145 McDonald JW Alvarez F Keller CA Pulmonary alveolar proteinosis in association with household exposure to fibrous insulation material. Chest. 2000;117(6):1813–1817. http://dx.doi.org/10.1378/chest.117.6.1813 10858425
146 Humble S Allan Tucker J Boudreaux C King JAC Snell K Titanium particles identified by energy-dispersive X-ray microanalysis within the lungs of a painter at autopsy. Ultrastruct Pathol. 2003;27(2):127–129. http://dx.doi.org/10.1080/01913120309925 12746205
147 Khan A Agarwal R Pulmonary alveolar proteinosis. Respir Care. 2011;56(7):1016–1028. http://dx.doi.org/10.4187/respcare.01125 21496372
148 Snipes MB Pulmonary retention of particles and fibers. In: McClellan RO Henderson RFeditors. Concepts in Inhalation Toxicology. 2nd ed. Boca Raton (FL): CRC Press; 1995. p. 225–256. http://dx.doi.org/10.1201/b14404-14
149 Miller FJ Dosimetry of particles in laboratory animals and humans in relationship to issues surrounding lung overload and human health risk assessment: a critical review. Inhal Toxicol. 2000;12(1-2):19–57. http://dx.doi.org/10.1080/089583700196536 10715617
150 Cullen RT Tran CL Buchanan D Davis JMG Searl A Jones AD Donaldson K Inhalation of poorly soluble particles. I. Differences in inflammatory response and clearance during exposure. Inhal Toxicol. 2000;12(12):1089–1111. http://dx.doi.org/10.1080/08958370050166787 11114783
151 Morrow PE Possible mechanisms to explain dust overloading of the lungs. Fundam Appl Toxicol. 1988;10(3):369–384. http://dx.doi.org/10.1016/0272-0590(88)90284-9 3286345
152 Tran CL Buchanan D Cullen RT Searl A Jones AD Donaldson K Inhalation of poorly soluble particles. II. Influence Of particle surface area on inflammation and clearance. Inhal Toxicol. 2000;12(12):1113–1126. http://dx.doi.org/10.1080/08958370050166796 11114784
153 Dahm MM Schubauer-Berigan MK Evans DE Birch ME Bertke S Beard JD Erdely A Fernback JE Mercer RR Grinshpun SA Exposure assessments for a cross-sectional epidemiologic study of US carbon nanotube and nanofiber workers. Int J Hyg Environ Health. 2018;221(3):429–440. https://doi.org/10.1016/j.ijheh.2018.01.006 29339022