# Discussion

The toxicity of inhaled multiwalled carbon nanotubes (MWCNTs) has been evaluated in several studies in rodents^51-56,65,99^; however, the physical aspects and purity of MWCNTs are diverse, and the critical physical and chemical properties associated with potential toxicity are currently unknown. The nonfunctionalized 1020 Long Multiwalled Carbon Nanotube (L-MWNT-1020) was selected for whole-body inhalation testing because large quantities of highly pure (98% pure) material are commercially available, and because L-MWNT-1020 is a long, thin, agglomerated MWCNT for which limited inhalation toxicity data are available. L-MWNT-1020 nanotubes are composed almost entirely of carbon and are stable and chemically unreactive. For these reasons, the potential pulmonary toxicity of L-MWNT-1020 is primarily a function of physical dimensions, exposure concentrations, and biopersistence. The potential toxicity of MWCNTs are a concern, in part, because their physical dimensions are similar to those of known toxic and carcinogenic fibers, such as asbestos.^4,100,101^ However, unlike relatively rigid and straight MWCNTs (e.g., Mitsui-7), the thinner and more flexible L-MWNT-1020 nanotubes (average 15 nm diameter and 2.6 µm long) form entangled agglomerates that are less likely to penetrate the pleura and produce asbestos-like pulmonary responses. The “cotton ball” agglomerates were a respirable size (less than 3 µm) with a “hairy” surface consisting of numerous ends of L-MWNT-1020. However, individual or small clusters of MWCNT would not be visible by light microscopy.^102^ Free L-MWNT-1020 agglomerates (i.e., not within macrophages or other cells) were not observed in or on the pleura of exposed animals in the current studies. The macrophages containing L-MWNT-1020 agglomerates that were seen in the pleural connective tissue or on the pleural surface were likely trafficking through the lymphatics to the bronchial and mediastinal lymph nodes, where similar macrophages were observed.

In the current studies, repeated inhalation exposures of rats and mice to L-MWNT-1020 resulted in increased lung weights and histopathologic lesions in the nose, larynx, lung, and bronchial and mediastinal lymph nodes without affecting animal survival. In general, histopathologic lesions occurred in animals exposed to 1 mg L-MWNT-1020/m^3^ or higher and progressed in incidences and/or severities with increasing exposure concentration. These target sites in the rodent respiratory tract are not unique to L-MWNT-1020 and have been observed in inhalation studies of agglomerated MWCNT,^49,52^ as well as more rigid, dispersed MWCNT.^42,56^

Chronic pulmonary inflammation was one of the most severe lesions in animals exposed to L-MWNT-1020. Mild to moderate chronic inflammation of the lung occurred in all rats and mice exposed to 3 or 10 mg/m^3^, and severity was minimal to mild in most animals exposed to 1 mg/m^3^. Pulmonary inflammation is the most reported effect of inhaled nanomaterials.^42,54-56,103-109^ In the current studies, chronic inflammation was characterized by increased numbers of macrophages in the alveoli, and clusters of neutrophils and macrophages mixed with cellular debris near alveolar ducts and terminal bronchioles. Because of their role in accumulating and removing particulate matter from the lung, alveolar macrophages and neutrophils are a major target of inhaled carbon nanotubes (CNT).^110^ Single or groups of agglomerated L-MWNT-1020 were observed in the cytoplasm of alveolar macrophages in exposed rats and mice. The persistence of indigestible materials in the phagolysosome has been associated with production of reactive oxygen species^111,112^ that may contribute to the inflammation and tissue damage caused by L-MWNT-1020. CNT also have been shown to stimulate macrophages to produce pro-inflammatory cytokines and chemokines.^56,113-118^ Although the mechanism is not clear, several studies suggest that CNT may trigger the activation of the Nlrp3 inflammasome complex in macrophages and other phagocytic cells, resulting in caspase-1-mediated activation and release of pro-inflammatory cytokines.^110,119-121^ The ensuing pulmonary inflammatory response normally results in clearance of the foreign particles, tissue repair, and recovery; however, repeated exposure to a biopersistent CNT like L-MWNT-1020 can result in chronic inflammation and tissue damage.^122^

The epithelium lining the respiratory tract received significant exposure to inhaled MWCNT. Histopathologic changes were observed in the epithelium of the nose, larynx, airways, and lungs of animals exposed to L-MWNT-1020. In the lung, minimal to mild alveolar (rats) and bronchiolar (mice) epithelial hyperplasia occurred in all animals exposed to 10 mg/m^3^, and in all rats and most mice exposed to 3 mg/m^3^. Alveolar epithelium hyperplasia is a proliferation of Type II epithelial cells, the precursors for Type I epithelial cells. Hyperplasia of Type II cells is often observed following injury and loss of Type I epithelial cells and is typically accompanied by inflammation.^123^ Direct evidence of epithelial cell damage, such as necrosis or degeneration, was not observed in the lungs of animals exposed to L-MWNT-1020. However, epithelial hyperplasia occurred concurrently with chronic inflammation, suggesting that the hyperplasia was a response to alveolar epithelial injury.

The most common pathologic findings in the respiratory tract of rodents exposed to chemicals by inhalation are those related to irritation of the nasal and laryngeal epithelium.^124^ Because rodents are obligate nose breathers, the nasal cavity is the major portal of entry for inhaled particles, and as the initial deposition site in the respiratory tract, the nose receives the highest concentrations of inhaled particulates. The only exposure-related effect observed in the nasal cavity of animals exposed to L-MWNT-1020 was a concentration-related increase in the incidences of hyaline droplet accumulation in the olfactory and respiratory epithelium. These lesions occurred at higher incidences in mice than in rats and were of minimal severity in both species. Hyaline droplet accumulation may have been the result of irritation of the nasal epithelium caused by the deposition and accumulation of L-MWNT-1020 nanotubes at these sites. The nasal mucosa is protected by a thin layer of mucus; however, penetration of the mucous layer by nanotubes is possible. Hyaline droplet accumulation in the nasal epithelium is commonly reported in rodent inhalation studies. Hyaline droplets are identified microscopically as eosinophilic inclusions in the cytoplasm of epithelial cells, and although their significance is unknown, they may reflect a defensive response to exposure.^125,126^ Hyaline droplet accumulation in the nasal cavity has been reported in inhalation studies of other MWCNT.^49,52,55,56^

The incidences of laryngeal epiglottal squamous metaplasia were significantly increased in a concentration-dependent manner in rats and mice exposed to 1 mg/m^3^ L-MWNT-1020 or greater. Squamous epithelium metaplasia of the larynx is one of the most commonly observed lesions in rodent inhalation studies,^127-129^ and the base of the epiglottis is the most sensitive region for development of squamous metaplasia in response to an irritant.^130,131^ Because the rodent larynx is nearly linear to the nasal turbinates, inhaled particles impact directly on the anterior surface of the larynx.^124^ Metaplasia is a common response to repeated irritation, and results in replacement of a sensitive epithelium by the more resistant squamous epithelium.^126,132^ Minimal squamous metaplasia of the larynx generally is considered an adaptive response, not an adverse effect.^129^ Laryngeal epiglottal squamous metaplasia has been noted in inhalation studies of other MWCNT.^52,55^

Pulmonary alveolar proteinosis (PAP) occurred in mice exposed to the two highest concentrations of L-MWNT-1020 but did not occur in rats. PAP is characterized by abnormal surfactant accumulation in the lungs potentially resulting in respiratory insufficiency.^133^ The most common clinical forms of this disease in humans are autoimmune PAP,^134^ and hereditary PAP^135,136^; however, PAP can also occur secondary to chronic dust exposure.^137^ Secondary PAP has been associated with human exposures to inorganic dusts (silica, cement, titanium, and aluminum), organic dusts (sawdust, fertilizer, bakery flour, and others), fumes (chlorine, varnish, and others), and fibers (cellulose insulation).^138-147^ The pathogenesis of secondary PAP is poorly understood but may be caused by increased surfactant production by alveolar Type II epithelial cells and/or decreased surfactant clearance due to macrophage impairment. Hyperplasia of Type II epithelium in mice exposed to L-MWNT-1020 may have resulted in increased production or decreased recycling of surfactant by these cells. In addition, macrophage clearance and catabolism of excess surfactant may have been inhibited by the accumulation of L-MWNT-1020 in the lungs. Macrophages laden with L-MWNT-1020 were observed in the lungs of exposed mice, especially at higher exposure concentrations. Repeated exposure to L-MWNT-1020 may have maintained the macrophage overload and further reduced surfactant clearance. One other MWCNT (Nanocyl^®^ NC7000^TM^) has been reported to cause PAP in male and female Wistar rats.^52^ Rats were exposed to Nanocyl aerosol (head-nose only) for 6 hours per day for 13 weeks at target concentrations of 0, 0.1, 0.5, or 2.5 mg/m^3^; PAP was diagnosed in rats exposed to 0.5 or 2.5 mg/m^3^. Nanocyl NC7000 is a long, thin MWCNT that forms respirable agglomerates, similar to L-MWNT-1020.

L-MWNT-1020 agglomerates and lymphoid hyperplasia were observed in the bronchial and mediastinal lymph nodes of exposed rats and mice. Both the amount of agglomerated L-MWNT-1020 and the incidences of lymphoid hyperplasia generally increased with increasing exposure concentration in the bronchial and mediastinal lymph nodes. Particles that deposit in the alveoli are normally engulfed by alveolar macrophages and then removed from the lung by mucociliary clearance or by migration to the pulmonary lymph nodes.^148,149^ However, during repeated exposure, if the rate of deposition exceeds the maximum rate of clearance, particles will accumulate until the ability of the macrophages to clear the particles is impaired. Impairment of macrophage function then leads to further accumulation of particles and lung overload.^47^

As summarized by Cullen et al.,^150^ hallmarks of lung overload by poorly soluble particles, such as L-MWNT-1020 include: persistent lung inflammation, increased epithelial proliferation, increased translocation of particles into the lung interstitial space and accumulation in lymph nodes, and decreased clearance of particles from the lung. In addition, alveolar macrophage clearance is compromised in lung overload when the volume of test material burden reaches approximately 6% of the total alveolar macrophage volume,^47,151^ or when the surface area exceeds the threshold for overload.^152^ In the current studies, most of these hallmarks occurred in rats and mice exposed to 3 mg/m^3^ of L-MWNT-1020 or greater. First, chronic active lung inflammation occurred in all rats and mice exposed to 3 or 10 mg/m^3^. Second, alveolar epithelium hyperplasia occurred in all rats exposed to 3 or 10 mg/m^3^ and bronchiolar epithelium hyperplasia occurred in all mice exposed to 10 mg/m^3^. Third, translocation of L-MWNT-1020 to mediastinal and/or bronchial lymph nodes was evident histologically in these groups. Fourth, clearance rates were progressively much slower for rats and mice exposed to 3 or 10 mg/m^3^, which supports impaired lung clearance in these groups. In addition, the L-MWNT-1020 lung burden volume and/or surface area required to reach overload was exceeded in the 3 and 10 mg/m^3^ exposure groups. Calculations based on L-MWNT-1020 surface area show that as little as 171 μg in rats or 14 to 22 μg in mice can result in the onset of lung overload; these levels of lung burden were achieved in both the 3 and 10 mg/m^3^ exposure groups. Similarly, calculations based on L-MWNT-1020 bulk particle density indicate that as little as 400 μg in rats, or 33 to 50 μg in mice can result in onset of lung overload; these levels of lung burden were achieved in the 10 mg/m^3^ exposure groups. Collectively, all these findings indicate that lung overload occurred in the current studies in groups of rats and mice exposed to 3 or 10 mg/m^3^_._

Few inhalation studies have measured lung burden and correlated lung overload with toxicity of MWCNT. Lung overload conditions were reported in one inhalation toxicity study of Baytubes, an agglomerated MWCNT.^49^ Male Wistar rats were exposed to 0, 0.1, 0.4, 1.5, or 6 mg/m^3^ of Baytubes for 6 hours per day, 5 days per week, for 13 weeks. Similar to the current studies, lung histopathology included parameters associated with inflammation, including focal-widespread terminal bronchiole/alveolus inflammatory cell influx, hypercellularity at the bronchoalveolar junction, interstitial thickening of the alveolus, and particle-laden macrophages. Terminal bronchiole/alveolus hyperplasia, although not observed after 13 weeks of exposure, was observed during the 26-week recovery period. Lung elimination half-lives for male rats were increased in a dose-dependent manner, and subsequent calculations suggest that severely impaired clearance or complete stasis occurred in the 1.5 and 6 mg/m^3^ exposure groups. Pauluhn concluded that the inflammation and toxicity observed in exposed animals were predominately due to lung overload rather than an intrinsic toxicity of the MWCNT, minimal to moderate lung overload occurred in the 0.1 and 0.4 mg/m^3^ exposure groups, and the no-observed-adverse-effect level was 0.1 mg/m^3^ based on the nasal and pulmonary responses.^49^

In this study, lung overload conditions were reached for groups exposed to 3 mg/m^3^ or greater and histopathology in these groups was generally consistent with an inflammatory response. Most of these lesions were also present in the 1 mg/m^3^ exposure groups, although the incidences and severities were generally lower. It is unclear to what extent, if any, lung burden contributed to the observed lesions. There were no significantly increased lesions in the respiratory tract of animals exposed to 0.3 mg/m^3^ or lower of L-MWNT-1020. Consistent with these results, 0.3 mg/m^3^ is considered the no-observed-adverse-effect level for L-MWNT-1020. Cumulatively, the histologic findings in the lungs of chronic active inflammation and alveolar/bronchiolar hyperplasia, the large lung burdens, the slow clearance rates, and lung burden volumes and surface areas above the thresholds for overload indicate that lung overload conditions occurred in animals exposed to 3 mg/m^3^ of L-MWNT-1020 or greater.

The lowest exposure concentration used in the 30-day studies (0.1 mg/m^3^) was the lowest achievable concentration that could be generated and monitored within the National Toxicology Program (NTP) specifications (±10%). These levels are also comparable to those used in the nose-only inhalation study of Pauluhn et al.^54^ (0.1–6 mg/m^3^) in which toxicological effects were noted. The exposure concentrations used in this study were approximately 100-fold higher than the NIOSH-proposed a recommended exposure limit for carbon nanotubes of 1 μg/m^3^ elemental carbon as a respirable mass 8-hour time-weighted average concentration.^36^ NIOSH researchers have also evaluated exposure in multiple U.S. manufacturers of CNTs and nanofibers and reported inhalable exposures of MWCNT of up to 0.4 mg/m.^3,153^ Given the long half-life and persistence of MWCNT in the lung, even short periods of exposure at such levels would lead to chronic high-level exposures. Therefore, although the no-observed-adverse-effect level determined in the present study (0.3 mg/m^3^) is approximately 300-fold higher than the recommended exposure limit, it is within the range observed in occupational settings and may be informative regarding potential health risks associated with occupational exposures to CNTs.