# Results

## Lung Burden Study in Rats

Summaries of body weights, lung weights, and lung burdens for male and female rats are presented in Table 2 and Table C-1. Lung weights in males were not significantly different from those in the chamber controls except in the 3 and 10 mg/m^3^ groups. In the male 3 and 10 mg/m^3^ dose groups, lung weights were significantly greater than those in the chamber control animals at 0 and 14 days postexposure. Likewise, lung weights in females were indistinguishable from chamber controls except in the 3 and 10 mg/m^3^ dose groups. In the female 3 and 10 mg/m^3^ dose groups, lung weights were significantly greater than those in the chamber control animals at 0 and 42 days postexposure. Increases in lung weights in the top two exposure concentration groups were resolved by the end of the postexposure period (126 days postexposure).

Table 2 Postexposure Lung Weights, Nickel Concentrations and Burdens, and 1020 Long Multiwalled Carbon Nanotube Burdens for Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
n
Day 0 | 10 | 10 | 10 | 10 | 10 | 10
Day 14 | 5 | 5 | 5 | 5 | 5 | 5
Day 42 | 5 | 5 | 5 | 5 | 5 | 5
Day 126 | 5 | 5 | 5 | 5 | 5 | 5
Male
Lung Weight (g)
Day 0 | 1.426 ± 0.047 | 1.511 ± 0.064 | 1.595 ± 0.105 | 1.599 ± 0.112 | 1.770 ± 0.054** | 1.782 ± 0.037**
Day 14 | 1.675 ± 0.214 | 1.807 ± 0.158 | 1.825 ± 0.036 | 1.752 ± 0.078 | 2.106 ± 0.075* | 2.286 ± 0.139**
Day 42 | 2.029 ± 0.180 | 1.772 ± 0.101 | 1.749 ± 0.076 | 2.123 ± 0.135 | 2.135 ± 0.147 | 1.973 ± 0.112
Day 126 | 1.996 ± 0.178 | 1.885 ± 0.056 | 2.009 ± 0.199 | 2.153 ± 0.208 | 2.191 ± 0.258 | 2.175 ± 0.068
Sample Concentration (µg Ni/g)
Day 0 | 0.001 ± 0.000 | 0.028 ± 0.001** | 0.095 ± 0.015** | 0.327 ± 0.019** | 0.818 ± 0.030** | 2.060 ± 0.102**
Day 14 | 0.001 ± 0.000 | 0.017 ± 0.001** | 0.052 ± 0.003** | 0.313 ± 0.019** | 0.721 ± 0.047** | 1.803 ± 0.082**^b^
Day 42 | 0.001 ± 0.000 | 0.012 ± 0.002** | 0.041 ± 0.004** | 0.204 ± 0.020** | 0.576 ± 0.060** | 1.657 ± 0.057**
Day 126 | 0.001 ± 0.000 | 0.005 ± 0.001** | 0.020 ± 0.005** | 0.097 ± 0.016** | 0.428 ± 0.062** | 1.426 ± 0.084**
Total Lung Burden (µg Ni/lung)
Day 0 | 0.001 ± 0.000 | 0.042 ± 0.002** | 0.141 ± 0.015** | 0.505 ± 0.018** | 1.439 ± 0.046** | 3.658 ± 0.163**
Day 14 | 0.002 ± 0.000 | 0.030 ± 0.003** | 0.095 ± 0.005** | 0.543 ± 0.018** | 1.523 ± 0.129** | 3.868 ± 0.115**^b^
Day 42 | 0.002 ± 0.001 | 0.020 ± 0.002** | 0.071 ± 0.006** | 0.430 ± 0.042** | 1.203 ± 0.092** | 3.258 ± 0.168**
Day 126 | 0.001 ± 0.000 | 0.010 ± 0.002** | 0.038 ± 0.006** | 0.201 ± 0.027** | 0.891 ± 0.091** | 3.095 ± 0.179**
Total Lung Burden (µg L-MWNT-1020/lung)
Day 0 | 0.192 ± 0.006 | 8.052 ± 0.405** | 27.10 ± 2.802** | 97.19 ± 3.421** | 276.8 ± 8.902** | 703.5 ± 31.28**
Day 14 | 0.323 ± 0.096 | 5.832 ± 0.641** | 18.24 ± 1.036** | 104.3 ± 3.377** | 292.9 ± 24.80** | 743.9 ± 22.07**^b^
Day 42 | 0.444 ± 0.180 | 3.858 ± 0.410** | 13.72 ± 1.248** | 82.64 ± 8.158** | 231.4 ± 17.66** | 626.5 ± 32.40**
Day 126 | 0.269 ± 0.024 | 1.907 ± 0.331** | 7.262 ± 1.074** | 38.74 ± 5.273** | 171.3 ± 17.49** | 595.3 ± 34.34**
Normalized Lung Burden (µg L-MWNT-1020/lung per mg/m^3^)
Day 0 | –^a^ | 80.52 ± 4.05 | 90.33 ± 9.34 | 97.19 ± 3.42 | 92.27 ± 2.97 | 70.35 ± 3.13
Day 14 | – | 58.32 ± 6.41 | 60.80 ± 3.45 | 104.35 ± 3.38 | 97.62 ± 8.27 | 74.39 ± 2.21^b^
Day 42 | – | 38.58 ± 4.10 | 45.73 ± 4.16 | 82.64 ± 8.16 | 77.13 ± 5.89 | 62.65 ± 3.24
Day 126 | – | 19.07 ± 3.31 | 24.21 ± 3.58 | 38.74 ± 5.27 | 57.09 ± 5.83 | 59.53 ± 3.43
Female
Lung Weight (g)
Day 0 | 1.230 ± 0.033 | 1.222 ± 0.050 | 1.200 ± 0.025 | 1.212 ± 0.035 | 1.378 ± 0.041** | 1.477 ± 0.040**
Day 14 | 1.452 ± 0.070 | 1.298 ± 0.107 | 1.330 ± 0.080 | 1.421 ± 0.088 | 1.428 ± 0.066 | 1.571 ± 0.041
Day 42 | 1.359 ± 0.062 | 1.324 ± 0.056 | 1.295 ± 0.034 | 1.371 ± 0.037 | 1.574 ± 0.087* | 1.509 ± 0.037*
Day 126 | 1.404 ± 0.058 | 1.457 ± 0.071 | 1.468 ± 0.082 | 1.397 ± 0.088 | 1.665 ± 0.152 | 1.715 ± 0.053
Sample Concentration (µg Ni/g)
Day 0 | 0.002 ± 0.000 | 0.026 ± 0.001** | 0.101 ± 0.009** | 0.374 ± 0.013** | 0.885 ± 0.028** | 2.351 ± 0.079**
Day 14 | 0.004 ± 0.002 | 0.022 ± 0.002** | 0.065 ± 0.007** | 0.285 ± 0.030** | 0.893 ± 0.048** | 2.117 ± 0.069**
Day 42 | 0.002 ± 0.001 | 0.015 ± 0.003** | 0.048 ± 0.005** | 0.268 ± 0.022** | 0.827 ± 0.101** | 2.147 ± 0.065**
Day 126 | 0.001 ± 0.000 | 0.005 ± 0.000** | 0.014 ± 0.002** | 0.105 ± 0.015** | 0.489 ± 0.083** | 1.776 ± 0.137**
Total Lung Burden (µg Ni/lung)
Day 0 | 0.002 ± 0.000 | 0.032 ± 0.001** | 0.120 ± 0.009** | 0.452 ± 0.018** | 1.212 ± 0.027** | 3.468 ± 0.138**
Day 14 | 0.006 ± 0.002 | 0.028 ± 0.002** | 0.085 ± 0.009** | 0.395 ± 0.022** | 1.276 ± 0.087** | 3.335 ± 0.189**
Day 42 | 0.003 ± 0.001 | 0.020 ± 0.004** | 0.062 ± 0.006** | 0.367 ± 0.034** | 1.301 ± 0.178** | 3.240 ± 0.139**
Day 126 | 0.002 ± 0.001 | 0.007 ± 0.000** | 0.020 ± 0.002** | 0.149 ± 0.029** | 0.774 ± 0.094** | 3.062 ± 0.291**
Total Lung Burden (µg L-MWNT-1020/lung)
Day 0 | 0.382 ± 0.092 | 6.177 ± 0.219** | 23.12 ± 1.778** | 86.94 ± 3.465** | 233.0 ± 5.252** | 666.9 ± 26.61**
Day 14 | 1.11 ± 0.37 | 5.34 ± 0.44** | 16.42 ± 1.70** | 76.00 ± 4.27** | 245.33 ± 16.71** | 641.37 ± 36.38**
Day 42 | 0.592 ± 0.243 | 3.756 ± 0.772** | 11.92 ± 1.146** | 70.65 ± 6.536** | 250.2 ± 34.24** | 623.1 ± 26.82**
Day 126 | 0.320 ± 0.133 | 1.320 ± 0.084** | 3.886 ± 0.437** | 28.59 ± 5.605** | 148.8 ± 18.10** | 588.8 ± 55.90**
Normalized Lung Burden (µg L-MWNT-1020/lung per mg/m^3^)
Day 0 | – | 61.77 ± 2.19 | 77.07 ± 5.93 | 86.94 ± 3.46 | 77.67 ± 1.75 | 66.69 ± 2.66
Day 14 | – | 53.44 ± 4.41 | 54.74 ± 5.65 | 76.00 ± 4.27 | 81.78 ± 5.57 | 64.14 ± 3.64
Day 42 | – | 37.56 ± 7.72 | 39.72 ± 3.82 | 70.65 ± 6.54 | 83.41 ± 11.41 | 62.31 ± 2.68
Day 126 | – | 13.20 ± 0.84 | 12.95 ± 1.46 | 28.59 ± 5.61 | 49.60 ± 6.03 | 58.88 ± 5.59

* Significantly different (p ≤ 0.05) from the chamber control group by Williams’ test.

** Significantly different (p ≤ 0.01) from the chamber control group by Williams’ test (lung weights) or Shirley’s test (other parameters).

^a^ Not applicable.

^b^ n = 4.

Normalized lung burdens generally decreased with increasing postexposure time but were quite variable across the exposed groups of males and females (Table 2). Although normalized lung burdens in groups exposed to higher concentrations generally decreased less with postexposure time compared to groups exposed to lower concentrations, no consistent trends toward increased or decreased normalized lung burdens were observed. This was likely due to high variability in the sample mean estimates, which were calculated from small sample sizes. The typical sample size for lung burden studies range from 5 to 10 animals per sex per exposure group.

### Lung Clearance Kinetics

Semilog plots of male and female rat lung burden versus days postexposure are presented in Figure C-1, Figure C-2, Figure C-3, Figure C-4, and Figure C-5. These plots also show the fit of the lung clearance model to the data; results of lung burden modeling are presented in Table 3.

Table 3 Lung Deposition and Clearance Parameter Estimates for Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

| 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
Male
Initial Lung Burden^a^ | 7.4 ± 0.7 | 23 ± 1 | 102 ± 3 | 278 ± 4 | 698 ± 7
k (days^−1^) | 0.013 ± 0.003 | 0.011 ± 0.002 | 0.0077 ± 0.0006 | 0.0043 ± 0.0003 | 0.0015 ± 0.0002
t_1/2_ (days) | 52 ± 10 | 64 ± 8 | 90 ± 6 | 160 ± 11 | 465 ± 48
Female
Initial Lung Burden | 6.1 ± 0.7 | 20 ± 1 | 87 ± 2 | 244 ± 4 | 652 ± 6
k (days^−1^) | 0.013 ± 0.003 | 0.013 ± 0.002 | 0.0092 ± 0.0007 | 0.0039 ± 0.0003 | 0.0012 ± 0.0002
t_1/2_ (days) | 54 ± 11 | 53 ± 7 | 76 ± 5 | 176 ± 13 | 583 ± 75

k = lung clearance rate constant from the model fit (days^−1^) ± standard deviation; t_1/2_ = lung clearance half-life (days) ± standard deviation.

^a^ Initial lung burden (at 0 days postexposure) extrapolated from the model fit (μg L-MWNT-1020/lung) presented as value ± standard deviation.

As shown in Figure C-1, Figure C-2, Figure C-3, Figure C-4, and Figure C-5, although there was considerable variability in the data, the model fits the data adequately. These figures also show that the slope of the line from the model fit decreases progressively as exposure concentrations increase, indicating significant decreases in the clearance rate constant with increasing exposure concentration.

### Lung Burden Modeling

Comparison of the model-estimated values of initial lung burdens in Table 3 with the lung burdens measured at the end of exposure (postexposure day 0; Table 2) indicates that the model-extrapolated burdens compare well with the actual lung burdens at that timepoint.

As shown in Table 3, the clearance rates are similar in the 0.1 and 0.3 mg/m^3^ exposure groups, indicating half-lives in the range of 52 to 64 days. However, starting with the 1 mg/m^3^ exposure group, clearance rates become progressively slower, with half-lives increasing to as long as 465 (males) or 583 (female) days in the 10 mg/m^3^ exposure groups. This slowing of the clearance rate with increasing exposure concentration is potentially a result of lung overload.

## Thirty-day Core Study in Rats

All core study animals survived to study termination (Table 4), and there were no treatment-related clinical observations. There were no statistically significant differences in body weight or body weight gain in any exposed group relative to the chamber controls (Table 4 and Figure 4).Upon gross examination, brown discoloration of the lungs was observed in most rats exposed to 3 mg/m^3^ of L-MWNT-1020 and all rats exposed to 10 mg/m^3^. In addition, the bronchial and mediastinal lymph nodes were enlarged and discolored (brown or gray) in all rats exposed to 10 mg/m^3^, in most rats exposed to 3 mg/m^3^, and in some rats exposed to 1 mg/m^3^.

Table 4 Survival and Body Weights of Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 125 ± 3 | 288 ± 6 | 164 ± 5
0.1 | 10/10 | 120 ± 2 | 291 ± 4 | 172 ± 3 | 101
0.3 | 10/10 | 117 ± 2 | 280 ± 5 | 163 ± 6 | 97
1 | 10/10 | 118 ± 3 | 282 ± 7 | 164 ± 6 | 98
3 | 10/10 | 123 ± 3 | 291 ± 4 | 168 ± 4 | 101
10 | 10/10 | 123 ± 3 | 289 ± 7 | 166 ± 7 | 100
Female
0 | 10/10 | 106 ± 2 | 194 ± 3 | 88 ± 2
0.1 | 10/10 | 108 ± 2 | 192 ± 5 | 84 ± 5 | 99
0.3 | 10/10 | 108 ± 3 | 195 ± 3 | 88 ± 2 | 101
1 | 10/10 | 108 ± 2 | 192 ± 3 | 84 ± 4 | 99
3 | 10/10 | 108 ± 2 | 195 ± 4 | 88 ± 3 | 101
10 | 10/10 | 104 ± 3 | 194 ± 4 | 90 ± 2 | 100

^a^ Weights and weight changes are given as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 31 (males) or 32 (females) days/number initially in group.

Figure 4

Growth Curves for Rats Exposed to 1020 Long Multiwalled Carbon Nanotubes by Inhalation for 30 Days

The absolute and relative lung weights were significantly greater in the 10 mg/m^3^ dose group of female rats compared to chamber controls (Table B-1). Treatment-related microscopic changes were seen in the organs examined (nose, larynx, lung, and lung-associated lymph nodes).

Nose: There were increases in the accumulation of hyaline droplets in the olfactory epithelium, and to a lesser extent in the respiratory epithelium of the nose, in male and female rats when compared to chamber controls. In all cases, the lesions were graded as minimal (Table 5, Table A-1, and Table A-2). These increases were not statistically significant, nor was there a strong association with exposure, but the highest exposure groups tended to have the highest incidences. Additionally, this is a common treatment-related finding in inhalation studies. Hyaline droplets in the olfactory epithelium were discrete accretions of brightly eosinophilic, homogeneous material that filled and expanded the cytoplasm of affected lining cells, often displacing the nucleus. Affected cells were very few in number and were located in short rows in the olfactory epithelium lining the ventral meatus in Level III. The overall extent of this especially subtle finding in rats was lower than that seen in the mice.

Table 5 Incidences of Nonneoplastic Lesions of the Respiratory System in Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
Male
Nose^a^ | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Accumulation, Hyaline Droplet^b^ | 0 | 1 (1.0)^c^ | 3 (1.0) | 0 | 0 | 3 (1.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 0 | 0 | 0 | 1 (1.0) | 1 (1.0)
Larynx | (10) | (10) | (10) | (10) | (10) | (10)
Epiglottis, Metaplasia, Squamous | 0 | 0 | 0 | 1 (1.0) | 9** (1.0) | 9** (1.0)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, Chronic | 5 (1.0) | 1 (1.0) | 2 (1.0) | 10* (1.0) | 10* (2.1) | 10* (3.0)
Alveolar Epithelium, Hyperplasia | 0 | 0 | 0 | 3 (1.0) | 10** (1.7) | 10** (1.9)
Female
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 1 (1.0) | 0 | 1 (1.0) | 1 (1.0) | 0 | 4 (1.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Larynx | (10) | (10) | (10) | (10) | (10) | (10)
Epiglottis, Metaplasia, Squamous | 0 | 1 (1.0) | 0 | 6** (1.0) | 9** (1.0) | 7** (1.0)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, Chronic | 0 | 3 (1.0) | 2 (1.0) | 6** (1.0) | 10** (1.8) | 10** (3.0)
Alveolar Epithelium, Hyperplasia | 0 | 0 | 0 | 2 (1.0) | 10** (1.1) | 10** (1.4)

* Significantly different (p ≤ 0.05) from the chamber control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Larynx: There were increases in the incidences of laryngeal epiglottic squamous metaplasia in male and female rats, although in all cases the severity grade was minimal (Table 5, Table A-1, and Table A-2). The incidences of epiglottic squamous metaplasia occurred with significant positive trends (p < 0.001) in males and females, and in females exposed to 1 mg/m^3^ of L-MWNT-1020 in males and females exposed to 3 and 10 mg/m^3^ the incidences were significantly increased compared to those in the chamber controls. Epiglottic squamous metaplasia was a subtle change in the lining epithelium at the base of the epiglottis. In affected animals, the normally cuboidal epithelium was focally replaced by a few layers of flattened, elongated, nonciliated, nonkeratinized, squamous cells. This change was always located in the central area of the epiglottic base.

Lung: There were exposure-related increases in the incidences of foreign body, chronic inflammation, and alveolar epithelial hyperplasia in both males and females. Foreign body was present in the lung of all exposed males and females, but in none of the chamber controls (Table A-1 and Table A-2). The average severity grade of the lesion in males and females increased with increasing exposure concentration above 0.3 mg/m^3^. The foreign body material consisted of variably abundant, homogeneous, black, discrete, nonbirefringent, round to irregularly shaped particles that ranged from less than 1 µm to approximately 4 µm. These particles occurred singly or often appeared to be in agglomerations of multiple particles. Although not visible by light microscope, the presence of individual MWCNTs cannot be discounted. In animals with minimal severity, the foreign bodies were extremely scarce, with only small numbers or single cytoplasmic particles in a few macrophages scattered through alveolar spaces. In mild to moderate cases, the material was more abundant. It was typically located in the cytoplasm of macrophages and even multinucleated giant cells (often constituent cells of the frequently concurrent chronic inflammation). Rarely, bronchiolar epithelial cells also contained small amounts of foreign body material. Clumps of extracellular foreign body material occasionally appeared to be free in alveolar spaces, bronchiolar lumens, and the otherwise unremarkable bronchial-associated lymphoid tissue (BALT). The foreign body material was presumed to be the test article, thus it was not considered a lesion and was not included in Table 5, but is shown in Table A-1 and Table A-2.

The incidences of chronic inflammation were significantly increased in males and females exposed to 1, 3, and 10 mg/m^3^ of L-MWNT-1020 (Table 5, Table A-1, and Table A-2). The chronic inflammation observed in the 0.1, 0.3, and 1 mg/m^3^ groups was minimal, as was that observed in five male chamber controls. No female chamber controls exhibited chronic inflammation. Severity of chronic inflammation increased with increasing exposure concentration from minimal to moderate across the 1, 3, and 10 mg/m^3^ dose groups of males and females. Chronic inflammation was characterized by increased numbers of diffusely scattered macrophages in alveoli and clusters or aggregates of neutrophils and cellular debris admixed with macrophages near alveolar ducts and terminal bronchioles. In exposed animals, the cytoplasm of these macrophages often contained variable amounts of foreign body material. In minimal cases, there were only minor increases in numbers of small macrophages, which were scattered singly or in small clusters mainly in the alveolar spaces with less involvement of the alveolar ducts or terminal bronchioles, and essentially no involvement of the more proximal airways. With increasing severity (mild to moderate), macrophages were still most abundant in the distal airways (alveolar ducts, terminal bronchioles), but also occurred occasionally in the lumens of larger bronchioles and bronchi, in the otherwise unremarkable BALT, in the pleural connective tissue, and very rarely appeared to be present on the pulmonary pleural surface. In addition, the macrophages in higher severity cases (notable in those with a moderate severity grade) were often large with vesicular nuclei and abundant pale pinkish cytoplasm containing multiple foreign body particles (including those in the pleural connective tissue or on the pleural surface); multinucleated giant cells were rarely present. Other features of chronic inflammation, especially in moderate cases, included slight focal thickening of scattered alveolar septa by infiltrates of small mononuclear cells. In some cases, slightly increased interstitial collagen fibers also contributed to the alveolar septal thickening. The small mononuclear cells occasionally formed narrow perivascular cuffs around smaller blood vessels. Small foci of extravasated red blood cells were occasionally noted in scattered alveolar spaces or in the perivascular stroma.

Alveolar epithelial hyperplasia was observed in three males and two females exposed to 1 mg/m^3^ of L-MWNT-1020 and in all males and females in the 3 and 10 mg/m^3^ groups (Table 5, Table A-1, and Table A-2). The average severity grades increased slightly with increasing exposure concentration in males and females. The incidences of alveolar epithelial hyperplasia in males and females exposed to 3 and 10 mg/m^3^ were significantly increased. Alveolar epithelial hyperplasia was characterized by short rows or clusters of crowded, plump, cuboidal epithelial cells along alveolar and alveolar duct walls that occasionally piled into multiple layers up to five cells thick. The alveolar epithelial hyperplasia was present concurrently with the chronic inflammation, suggesting that the hyperplasia was a response to alveolar epithelial injury.

Bronchial and mediastinal lymph nodes: In male and female rats, foreign body material was observed in the bronchial and mediastinal lymph nodes (Table A-1 and Table A-2). The foreign body was morphologically identical to that seen in the lungs and is presumed to be the test article. The foreign body was not considered a lesion so it was not included in Table 6. The presence of foreign body generally increased in incidence with increasing exposure concentration in the bronchial and mediastinal lymph nodes, in both males and females. The incidences of foreign body in both sexes and both lymph nodes were significantly increased in the 1, 3, and 10 mg/m^3^ exposure groups, except for the mediastinal lymph node in male rats exposed to 1 mg/m^3^ of L-MWNT-1020. It was present mainly in macrophages within the paracortex and medullary cords, but there was some extracellular foreign material in the paracortex. The incidences of lymphoid hyperplasia in both lymph nodes were significantly increased in males and females exposed to 3 and 10 mg/m^3^ (except bronchial lymph node in males exposed at 10 mg/m^3^) as was the incidence in the mediastinal lymph node of female rats exposed to 1 mg/m^3^ (Table 6, Table A-1, and Table A-2). The severity of lymphoid hyperplasia generally increased with increasing exposure concentration Table 6.

Table 6 Incidences of Nonneoplastic Lesions of the Bronchial and Mediastinal Lymph Nodes in Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
Male
Lymph Node, Bronchial^a^ | (6) | (6) | (9) | (7) | (7) | (7)
Hyperplasia, Lymphoid^b^ | 0 | 0 | 0 | 0 | 6** (2.0)^c^ | 2 (1.5)
Lymph Node, Mediastinal | (7) | (9) | (10) | (9) | (9) | (10)
Hyperplasia, Lymphoid | 0 | 3 (1.7) | 1 (1.0) | 3 (1.3) | 8** (2.1) | 9** (2.7)
Female
Lymph Node, Bronchial | (7) | (6) | (4) | (6) | (7) | (9)
Hyperplasia, Lymphoid | 0 | 1 (1.0) | 0 | 2 (1.5) | 6** (1.7) | 7** (2.6)
Lymph Node, Mediastinal | (10) | (10) | (9) | (10) | (10) | (10)
Hyperplasia, Lymphoid | 2 (1.0) | 3 (1.0) | 3 (1.7) | 7* (2.0) | 9** (2.8) | 10** (3.4)

* Significantly different (p ≤ 0.05) from the chamber control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

The lymphoid hyperplasia was characterized primarily by increased numbers of well-differentiated, medium-sized to large mature lymphocytes in the paracortex and medullary cords. More severe cases sometimes also had more prominent cortical germinal centers. The enlargement of the bronchial and mediastinal lymph nodes seen at necropsy was attributed to the lymphoid hyperplasia.

## Lung Burden Study in Mice

Summaries of body weights, lung weights, and lung burdens for male and female tissue burden study mice are presented in Table 7 and Table C-2. Lung weights for males and females exposed to 3 or 10 mg/m^3^ were significantly greater than those in the chamber control groups on the last exposure day (postexposure day 0) and remained significantly greater throughout the postexposure period. The lung weight for females exposed to 1 mg/m^3^ was significantly increased relative to the chamber control group at postexposure day 0, but not significantly different at any later postexposure timepoint.

Table 7 Postexposure Lung Weights, Nickel Concentrations and Burdens, and 1020 Long Multiwalled Carbon Nanotube Burdens for Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
n
Day 0 | 10 | 10 | 10 | 10 | 10 | 10
Day 14 | 5 | 5 | 5 | 5 | 5 | 5
Day 42 | 5 | 5 | 5 | 5 | 5 | 5
Day 126 | 5 | 5 | 5 | 5 | 5 | 5
Male
Lung Weight (g)
Day 0 | 0.153 ± 0.003 | 0.155 ± 0.004 | 0.149 ± 0.002 | 0.160 ± 0.003 | 0.181 ± 0.004** | 0.224 ± 0.003**
Day 14 | 0.164 ± 0.006 | 0.160 ± 0.005 | 0.165 ± 0.008 | 0.170 ± 0.001 | 0.190 ± 0.003* | 0.274 ± 0.012**
Day 42 | 0.149 ± 0.002 | 0.143 ± 0.002 | 0.150 ± 0.004 | 0.155 ± 0.003 | 0.182 ± 0.004** | 0.237 ± 0.007**
Day 126 | 0.175 ± 0.006 | 0.166 ± 0.008 | 0.175 ± 0.004 | 0.172 ± 0.004 | 0.197 ± 0.002** | 0.231 ± 0.003**
Sample Concentration (µg Ni/g)
Day 0 | 0.016 ± 0.008 | 0.053 ± 0.003** | 0.180 ± 0.036** | 0.546 ± 0.014** | 1.324 ± 0.033** | 2.582 ± 0.075**
Day 14 | 0.065 ± 0.054 | 0.035 ± 0.006 | 0.092 ± 0.010* | 0.403 ± 0.025** | 1.115 ± 0.042** | 2.045 ± 0.199**
Day 42 | 0.028 ± 0.009 | 0.053 ± 0.013 | 0.066 ± 0.007* | 0.267 ± 0.025** | 1.001 ± 0.046** | 2.356 ± 0.082**
Day 126 | 0.008 ± 0.000 | 0.008 ± 0.000 | 0.021 ± 0.008* | 0.220 ± 0.017** | 0.907 ± 0.034** | 1.900 ± 0.043**
Total Lung Burden (µg Ni/lung)
Day 0 | 0.002 ± 0.001 | 0.008 ± 0.000** | 0.027 ± 0.005** | 0.087 ± 0.002** | 0.239 ± 0.005** | 0.578 ± 0.017**
Day 14 | 0.011 ± 0.009 | 0.006 ± 0.001 | 0.015 ± 0.001* | 0.069 ± 0.004** | 0.212 ± 0.008** | 0.551 ± 0.034**
Day 42 | 0.004 ± 0.001 | 0.008 ± 0.002 | 0.010 ± 0.001* | 0.042 ± 0.004** | 0.183 ± 0.010** | 0.557 ± 0.015**
Day 126 | 0.001 ± 0.000 | 0.001 ± 0.000 | 0.004 ± 0.001 | 0.038 ± 0.003** | 0.179 ± 0.008** | 0.438 ± 0.014**
Total Lung Burden (µg L-MWNT-1020/lung)
Day 0 | 0.46 ± 0.23 | 1.57 ± 0.08** | 5.11 ± 0.96** | 16.81 ± 0.42** | 45.97 ± 0.92** | 111.09 ± 3.18**
Day 14 | 2.11 ± 1.76 | 1.11 ± 0.21 | 2.88 ± 0.26* | 13.20 ± 0.84** | 40.78 ± 1.51** | 105.93 ± 6.53**
Day 42 | 0.79 ± 0.25 | 1.45 ± 0.33 | 1.89 ± 0.17* | 7.98 ± 0.84** | 35.15 ± 1.87** | 107.15 ± 2.85**
Day 126 | 0.27 ± 0.01 | 0.26 ± 0.01 | 0.72 ± 0.27 | 7.29 ± 0.62** | 34.45 ± 1.63** | 84.31 ± 2.61**
Normalized Lung Burden (µg L-MWNT-1020/lung per mg/m^3^)
Day 0 | –^a^ | 15.73 ± 0.83 | 17.03 ± 3.21 | 16.81 ± 0.42 | 15.32 ± 0.31 | 11.11 ± 0.32
Day 14 | – | 11.07 ± 2.15 | 9.61 ± 0.88 | 13.20 ± 0.84 | 13.59 ± 0.50 | 10.59 ± 0.65
Day 42 | – | 14.46 ± 3.34 | 6.29 ± 0.56 | 7.98 ± 0.84 | 11.72 ± 0.62 | 10.72 ± 0.28
Day 126 | – | 2.56 ± 0.13 | 2.39 ± 0.88 | 7.29 ± 0.62 | 11.48 ± 0.54 | 8.43 ± 0.26
Female
Lung Weight (g)
Day 0 | 0.148 ± 0.002 | 0.154 ± 0.002 | 0.156 ± 0.003 | 0.161 ± 0.002** | 0.181 ± 0.003** | 0.215 ± 0.003**
Day 14 | 0.159 ± 0.004 | 0.154 ± 0.003 | 0.158 ± 0.004 | 0.165 ± 0.002 | 0.185 ± 0.006** | 0.252 ± 0.008**
Day 42 | 0.163 ± 0.003 | 0.162 ± 0.005 | 0.168 ± 0.004 | 0.167 ± 0.003 | 0.194 ± 0.004** | 0.232 ± 0.006**
Day 126 | 0.174 ± 0.003 | 0.166 ± 0.005 | 0.164 ± 0.003 | 0.167 ± 0.003 | 0.191 ± 0.006** | 0.239 ± 0.004**
Sample Concentration (µg Ni/g)
Day 0 | 0.008 ± 0.000 | 0.056 ± 0.005** | 0.121 ± 0.004** | 0.494 ± 0.016** | 1.168 ± 0.030** | 2.609 ± 0.056**
Day 14 | 0.013 ± 0.005 | 0.065 ± 0.029* | 0.085 ± 0.011** | 0.443 ± 0.039** | 1.109 ± 0.040** | 2.275 ± 0.059**
Day 42 | 0.013 ± 0.005 | 0.037 ± 0.018 | 0.062 ± 0.006** | 0.302 ± 0.013** | 1.034 ± 0.017** | 2.448 ± 0.039**
Day 126 | 0.008 ± 0.000 | 0.016 ± 0.008 | 0.021 ± 0.004* | 0.092 ± 0.007** | 0.907 ± 0.036** | 2.060 ± 0.069**
Total Lung Burden (µg Ni/lung)
Day 0 | 0.001 ± 0.000 | 0.009 ± 0.001** | 0.019 ± 0.000** | 0.079 ± 0.002** | 0.212 ± 0.007** | 0.561 ± 0.013**
Day 14 | 0.002 ± 0.001 | 0.010 ± 0.005* | 0.013 ± 0.002** | 0.073 ± 0.007** | 0.204 ± 0.007** | 0.573 ± 0.013**
Day 42 | 0.002 ± 0.001 | 0.006 ± 0.003 | 0.010 ± 0.001** | 0.050 ± 0.002** | 0.201 ± 0.006** | 0.568 ± 0.014**
Day 126 | 0.001 ± 0.000 | 0.003 ± 0.002 | 0.003 ± 0.001 | 0.015 ± 0.001** | 0.173 ± 0.007** | 0.491 ± 0.011**
Total Lung Burden (µg L-MWNT-1020/lung)
Day 0 | 0.23 ± 0.00 | 1.67 ± 0.15** | 3.61 ± 0.07** | 15.25 ± 0.37** | 40.80 ± 1.32** | 107.88 ± 2.53**
Day 14 | 0.40 ± 0.15 | 1.92 ± 0.87* | 2.59 ± 0.30** | 14.10 ± 1.31** | 39.31 ± 1.39** | 110.13 ± 2.59**
Day 42 | 0.41 ± 0.16 | 1.14 ± 0.56 | 2.00 ± 0.16** | 9.66 ± 0.46** | 38.58 ± 1.07** | 109.27 ± 2.74**
Day 126 | 0.27 ± 0.00 | 0.54 ± 0.29 | 0.67 ± 0.14 | 2.95 ± 0.24** | 33.33 ± 1.34** | 94.39 ± 2.14**
Normalized Lung Burden (µg L-MWNT-1020/lung per mg/m^3^)
Day 0 | – | 16.69 ± 1.48 | 12.05 ± 0.24 | 15.25 ± 0.37 | 13.60 ± 0.44 | 10.79 ± 0.25
Day 14 | – | 19.18 ± 8.70 | 8.63 ± 1.01 | 14.10 ± 1.31 | 13.10 ± 0.46 | 11.01 ± 0.26
Day 42 | – | 11.36 ± 5.62 | 6.68 ± 0.54 | 9.66 ± 0.46 | 12.86 ± 0.36 | 10.93 ± 0.27
Day 126 | – | 5.41 ± 2.92 | 2.23 ± 0.47 | 2.95 ± 0.24 | 11.11 ± 0.45 | 9.44 ± 0.21

* Significantly different (p ≤ 0.05) from the chamber control group by Williams’ test (lung weights) or Shirley’s test (other parameters).

** p ≤ 0.01.

^a^ Not applicable.

Normalized lung burdens generally decreased with increasing postexposure time but were quite variable across the exposed groups of males and females (Table 7). Although normalized lung burdens in groups exposed to higher concentrations generally decreased less with postexposure time compared to groups exposed to lower concentrations, no consistent trends toward increased or decreased normalized lung burdens were observed. This was likely due to high variability in the sample mean estimates, which were calculated from small sample sizes. The typical sample size for lung burden studies range from 5 to 10 animals per sex per group.

### Lung Clearance Kinetics

Semilog plots of male and female lung burden versus days postexposure are presented in Figure C-6, Figure C-7, Figure C-8, Figure C-9, and Figure C-10. These plots also show the fit of the lung clearance model to the data; results of lung burden modeling are presented in Table 8.

Table 8 Lung Deposition and Clearance Parameter Estimates for Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

| 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
Male
Initial Lung Burden^a^ | 1.4 ± 0.4 | 4 ± 1 | 15 ± 1 | 43 ± 2 | 111 ± 3
k (days^−1^) | 0.007 ± 0.01 | 0.015 ± 0.006 | 0.0085 ± 0.002 | 0.0024 ± 0.0007 | 0.0021 ± 0.0004
t_1/2_ (days) | 96 ± 61 | 47 ± 13 | 82 ± 14 | 293 ± 70 | 337 ± 59
Female
Initial Lung Burden | 1.4 ± 0.4 | 3 ± 1 | 16 ± 1 | 40 ± 2 | 110 ± 3
k (days^−1^) | 0.010 ± 0.01 | 0.013 ± 0.005 | 0.013 ± 0.002 | 0.0015 ± 0.0007 | 0.0011 ± 0.0004
t_1/2_ (days) | 70 ± 38 | 53 ± 14 | 54 ± 7 | 448 ± 141 | 649 ± 183

k = lung clearance rate constant from the model fit (days^−1^) ± standard deviation; t_1/2_ = lung clearance half-life (days) ± standard deviation.

^a^ Initial lung burden (at 0 days postexposure) extrapolated from the model fit (μg L-MWNT-1020/lung) presented as value ± standard deviation.

As shown in Figure C-6, Figure C-7, Figure C-8, Figure C-9, and Figure C-10, although there was considerable variability in the data, the model fits the data adequately. These figures also show that the slope of the line from the model fit progressively decreases as exposure concentrations increase, indicating significant decreases in the clearance rate constant with increasing exposure concentration.

### Lung Burden Modeling

Comparison of model-estimated values of initial lung burdens in Table 8 with the lung burdens measured at the end of exposure (postexposure day 0; Table 7) indicates that the model-extrapolated burdens compare well with the actual lung burdens at that timepoint and increased approximately in proportion to exposure concentration.

As shown in Table 8, the clearance rates are similar in the 0.1, 0.3, and 1 mg/m^3^ exposure groups, indicating half-lives in the range of 47 to 96 days. However, starting with the 3 mg/m^3^ exposure group, clearance rates become progressively slower, with half-lives increasing to as long as 337 (males) to 649 (females) days in the 10 mg/m^3^ exposure groups. This slowing of the clearance rate with increasing exposure concentration is potentially a result of lung overload.

## Thirty-day Core Study in Mice

All core study animals survived to study termination (Table 9), and there were no treatment-related clinical observations. There were no statistically significant differences in body weight or body weight gain in any exposed group relative to the chamber controls (Table 9 and Figure 5). Grossly, brown discoloration of the lungs was observed in male and female mice exposed to 3 or 10 mg/m^3^. In addition, brown discoloration of bronchial and mediastinal lymph nodes was observed in most exposed female mice and all male mice exposed to 3 or 10 mg/m^3^.

Table 9 Survival and Body Weights of Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 22.6 ± 0.3 | 27.9 ± 0.4 | 5.3 ± 0.2
0.1 | 10/10 | 22.3 ± 0.4 | 27.6 ± 0.3 | 5.3 ± 0.4 | 99
0.3 | 10/10 | 22.3 ± 0.4 | 27.3 ± 0.5 | 5.1 ± 0.3 | 98
1 | 10/10 | 22.2 ± 0.3 | 27.2 ± 0.3 | 5.0 ± 0.3 | 97
3 | 10/10 | 22.2 ± 0.4 | 27.5 ± 0.5 | 5.3 ± 0.4 | 99
10 | 10/10 | 22.6 ± 0.3 | 27.8 ± 0.5 | 5.2 ± 0.2 | 100
Female
0 | 10/10 | 19.1 ± 0.3 | 24.4 ± 0.5 | 5.4 ± 0.4
0.1 | 10/10 | 19.0 ± 0.2 | 24.1 ± 0.3 | 5.1 ± 0.3 | 98
0.3 | 10/10 | 19.4 ± 0.3 | 24.5 ± 0.4 | 5.1 ± 0.3 | 100
1 | 10/10 | 19.4 ± 0.2 | 24.7 ± 0.3 | 5.4 ± 0.4 | 101
3 | 10/10 | 18.6 ± 0.2 | 23.8 ± 0.3 | 5.2 ± 0.3 | 97
10 | 10/10 | 19.0 ± 0.2 | 24.8 ± 0.3 | 5.8 ± 0.2 | 101

^a^ Weights and weight changes are given as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 31 (males) or 32 (females) days/number initially in group.

Figure 5

Growth Curves for Mice Exposed to 1020 Long Multiwalled Carbon Nanotubes by Inhalation for 30 Days

Compared to those of the chamber controls, the absolute and relative lung weights were significantly greater in male and female mice exposed to 3 or 10 mg/m^3^ of L-MWNT-1020 (Table B-2). Treatment-related microscopic changes were seen in the organs examined (nose, larynx, lung, and lung-associated lymph nodes).

Nose: The incidences of accumulation of hyaline droplets in the olfactory epithelium were significantly increased in females exposed to 3 mg/m^3^ of L-MWNT-1020 and in males and females exposed to 10 mg/m^3^, and the incidences of this lesion in the respiratory epithelium were significantly increased in females exposed to 1 mg/m^3^ and in males and females exposed to 3 and 10 mg/m^3^ (Table 10, Table A-3, and Table A-4). The average severity grade of these lesions increased in the 10 mg/m^3^ exposure groups. Overall, this response was more extensive in mice than in the rats. The morphologic appearance of the hyaline droplets was identical to that seen in the rats. In mice, they occurred most commonly at the junction of the respiratory and olfactory epithelia along the septum and nasoturbinates in Level 2 and in the ventral half of Level 3.

Table 10 Incidences of Nonneoplastic Lesions of the Respiratory System in Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
Male
Nose^a^ | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Accumulation, Hyaline Droplet^b^ | 0 | 0 | 0 | 0 | 2 (1.0)^c^ | 9** (1.2)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 0 | 0 | 3 (1.0) | 9** (1.0) | 10** (1.6)
Larynx | (9) | (10) | (10) | (10) | (10) | (10)
Epiglottis, Metaplasia, Squamous^c^ | 1 (1.0) | 2 (1.0) | 3 (1.0) | 6* (1.0) | 9** (1.1) | 10** (1.4)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, Chronic | 0 | 0 | 0 | 8** (1.0) | 10** (1.2) | 10** (2.6)
Alveolus, Proteinosis | 0 | 0 | 0 | 0 | 3 (1.0) | 10** (1.9)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 7** (1.0) | 10** (1.6)
Female
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 0 | 0 | 1 (1.0) | 3 (1.0) | 8** (1.0) | 10** (1.8)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 0 | 0 | 8** (1.0) | 10** (1.1) | 10** (2.0)
Larynx | (10) | (10) | (10) | (10) | (10) | (10)
Epiglottis, Metaplasia, Squamous | 1 (1.0) | 1 (1.0) | 1 (1.0) | 4 (1.0) | 6* (1.0) | 10** (1.9)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, Chronic | 0 | 0 | 0 | 4* (1.0) | 10** (1.3) | 10** (2.8)
Alveolus, Proteinosis | 0 | 0 | 0 | 0 | 9** (1.0) | 10** (1.6)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 6** (1.0) | 10** (1.3)

* Significantly different (p ≤ 0.05) from the chamber control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Larynx: There were significant increases in the incidences of epiglottic squamous metaplasia in the larynges of males exposed to 1 mg/m^3^ and males and females exposed to 3 and 10 mg/m^3^ of L-MWNT-1020 (Table 10, Table A-3, and Table A-4). In males, the incidences increased with increasing exposure concentration, and the severity (minimal to mild) increased slightly in the 3 and 10 mg/m^3^ exposure groups. In females, the incidences increased with increasing exposure concentration beginning at 1 mg/m^3^, and the severity increased from minimal in the 3 mg/m^3^ exposure group to mild in the 10 mg/m^3^ exposure group. Epiglottic squamous metaplasia was localized to the base of the epiglottis and was characterized by replacement of the normal, ciliated columnar epithelium by a stratified squamous epithelium composed of aciliate, polygonal to flattened cells with variable keratinization. The metaplastic squamous epithelium was as thick as four to six cell layers in the most severe cases.

Lung: There were exposure-related increases in the incidences of foreign body, chronic inflammation, alveolar proteinosis, and bronchiolar epithelial hyperplasia in both males and females (Table 10, Table A-3, and Table A-4). Foreign body occurred in all exposed males and females, except for one animal each in the male and female 0.1 mg/m^3^ exposure groups. Foreign body was not observed in the chamber controls. Foreign body accumulation was minimal in the 0.1 and 0.3 mg/m^3^ exposure groups and increased with increasing exposure concentration in the higher exposure groups. The foreign body material was morphologically identical to that seen in rats. It was found in the cytoplasm of bronchiolar and alveolar lining cells, alveolar macrophages, and multinucleated giant cells, and free within the bronchiolar lumina and alveolar spaces. The foreign body material was presumed to be the test article, thus it was not considered a lesion and was not included in Table 10 but is shown in Table A-3 and Table A-4.

Chronic inflammation occurred in males and females exposed to 1, 3, and 10 mg/m^3^ of L-MWNT-1020, and the incidences were significantly increased compared to those in the chamber controls where the lesion did not occur (Table 10, Table A-3, and Table A-4). The chronic inflammation observed was similar to that seen in rats. In mice, macrophages were occasionally seen in the lymphatics adjacent to small blood vessels. Alveoli containing clumps of macrophages were noted throughout the lobar parenchyma, but there was a tendency, especially in moderate cases, for large clusters of macrophages to occur in alveoli directly subjacent to the pleura. Unlike the rats, macrophages were not noted in BALT, pulmonary connective tissue, or the pleural surface.

Alveolar proteinosis occurred in three male mice exposed to 3 mg/m^3^ and nine female mice exposed to 3 mg/m^3^ of L-MWNT-1020, and in all males and females exposed to 10 mg/m^3^ (Table 10, Table A-3, and Table A-4). The incidences in females exposed to 3 mg/m^3^ and males and females exposed to 10 mg/m^3^ were significantly increased compared to those in the chamber controls. The severity of the alveolar proteinosis was minimal in the 3 mg/m^3^ exposure groups but increased in males and female exposed to 10 mg/m^3^. Alveolar proteinosis was characterized as aggregates of finely granular, pale eosinophilic material in the alveolar spaces, occasionally in the alveolar ducts, and very rarely in the terminal bronchioles. It was often intermingled with, but always clearly distinct from, the intraluminal black foreign body material.

Bronchiolar epithelial hyperplasia occurred in only males and females exposed to 3 and 10 mg/m^3^, and the incidences were significantly increased compared to those in the chamber controls (Table 10, Table A-3, and Table A-4). Bronchiolar epithelial hyperplasia was a minimal to mild change that affected only some airways in a given lung and was most prominent in the smaller and terminal bronchioles. Compared to the chamber controls, the lining epithelium of scattered terminal bronchioles in affected lungs had focal to confluent areas with increased numbers of plump, variably ciliated, cuboidal cells, often crowded into multiple layers two to five cells thick or even forming small papillary projections. These hyperplastic cells sometimes extended from the terminal bronchioles to line the adjacent alveolar ducts, but this was uncommon. Small focal areas of hyperplastic cells were also noted occasionally in the lining epithelium of larger bronchioles.

Bronchial and mediastinal lymph nodes: In male and female mice, foreign body and lymphoid hyperplasia were observed in the bronchial and mediastinal lymph nodes (Table 11, Table A-3, and Table A-4). In males, the incidences of foreign body were significantly increased in the bronchial lymph node in the 1, 3, and 10 mg/m^3^ exposure groups compared to the chamber controls. In females, foreign body was significantly increased in the 3 and 10 mg/m^3^ exposure groups in the bronchial lymph node and in the 10 mg/m^3^ exposure group in the mediastinal lymph node compared to the chamber controls. The severity of the foreign body in both lymph nodes of males and females was minimal, with the exception of the bronchial lymph node in males exposed to 10 mg/m^3^ in which one animal had mildly severe foreign body occurrence. The foreign body material was morphologically identical to that seen in the lungs of the rats and mice and in the lung-associated lymph nodes in rats; because the material was not seen in controls, it is presumed to be the test article. It was located in a few, widely scattered resident macrophages in the paracortex and medullary cords or apparently extracellular in the paracortex. Foreign body was not considered a lesion so it was not included in Table 11 but is shown in Table A-3 and Table A-4.

Table 11 Incidences of Nonneoplastic Lesions of the Bronchial and Mediastinal Lymph Nodes in Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
Male
Lymph Node, Bronchial^a^ | (6) | (9) | (7) | (7) | (9) | (7)
Hyperplasia, Lymphoid^b^ | 0 | 0 | 0 | 2 (1.0)^c^ | 5* (1.8) | 3 (1.7)
Lymph Node, Mediastinal | (9) | (7) | (8) | (10) | (9) | (9)
Hyperplasia, Lymphoid | 0 | 0 | 0 | 1 (2.0) | 1 (3.0) | 3 (2.7)
Female
Lymph Node, Bronchial | (9) | (3) | (8) | (9) | (6) | (6)
Hyperplasia, Lymphoid | 1 (1.0) | 0 | 0 | 2 (1.0) | 3 (1.3) | 5* (1.8)
Lymph Node, Mediastinal | (7) | (8) | (8) | (7) | (10) | (9)
Hyperplasia, Lymphoid | 0 | 0 | 0 | 1 (2.0) | 1 (2.0) | 5* (1.4)

* Significantly different (p ≤ 0.05) from the chamber control group by the Fisher exact test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In males, lymphoid hyperplasia of the bronchial and mediastinal lymph nodes occurred in the 1, 3, and 10 mg/m^3^ exposure groups and was not observed in chamber controls (Table 11 and Table A-3). The incidence of bronchial lymphoid hyperplasia in males exposed to 3 mg/m^3^ was significantly increased compared to that in the chamber controls. The severity of this lesion in males tended to increase with increasing exposure concentration, although there was a slight decrease in severity in the 10 mg/m^3^ exposure group compared to the 3 mg/m^3^ exposure group. In females, lymphoid hyperplasia of the bronchial and mediastinal lymph nodes occurred in the 1, 3, and 10 mg/m^3^ exposure groups; one chamber control female had lymphoid hyperplasia in the bronchial lymph node (Table 11 and Table A-4). In females exposed to 10 mg/m^3^, the incidences of lymphoid hyperplasia in both lymph nodes were significantly increased compared to those in the chamber controls. As with the males, the severity of the lesion tended to increase with increasing exposure concentration.

Lymphoid hyperplasia in both lymph nodes and in both sexes was characterized by increased numbers of well-differentiated, medium-sized to large lymphocytes primarily in the paracortex and to a lesser extent in the medullary cords (Table 11, Table A-3, and Table A-4).