# Materials and Methods

## Procurement and Characterization of 1020 Long Multiwalled Carbon Nanotubes

The test material—1020 Long Multiwalled Carbon Nanotube (L-MWNT-1020) nominal 10–20 nm outer diameter, 10–30 µm long multiwalled carbon nanotube (MWCNT)—was obtained from Sun Innovations, Inc. (Fremont, CA) in one lot (supplier item number SN9847, supplier lot number 10031301M) and was used in the 30-day studies. The study laboratory, Battelle Toxicology Northwest (Richland, WA), assigned the numbers 1 through 12 to the 12 amber glass containers received from the supplier. Identity and purity analyses were conducted by various analytical chemistry laboratories and by the study laboratory (Appendix D). Reports on analyses performed in support of the L-MWNT-1020 studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot 10031301M of the chemical, a dull black powder, was characterized by Environmental Molecular Sciences Laboratory (EMSL) at Pacific Northwest National Laboratory (PNNL) (Richland, WA) using transmission electron microscopy (TEM), scanning electron microscopy (SEM), Raman spectroscopy, energy dispersive X-ray spectroscopy (EDS), and X-ray photoelectron spectroscopy (XPS). In addition, lot 10031301M was characterized by Elemental Analysis, Inc. (Lexington, KY) using neutron activation analysis (NAA) and by Quantachrome Instruments (Boynton Beach, FL) using helium gas pycnometry (skeletal density), electrophoretic velocimetry (zeta potential), and Brunauer-Emmett-Teller (BET) gas adsorption analysis (surface area). TEM images confirmed test material identity by visualizing agglomerates of MWCNTs and determined an average nanotube diameter of 15.3 nm (range: 6.1 to 26.7 nm) (Figure 2). SEM estimated an average nanotube length of 2.6 µm (range: 0.6 to 7.4 µm) (Figure 2). These averages (length of 2,600 nm and width of 15.3 nm) yielded an estimated length:width aspect ratio of 170:1 for the nanotubes in lot 10031301M. Raman spectra of lot 10031301M contained spectral features consistent with those seen in spectra for commercially procured standards of similar graphitic materials, including G,G′, and D bands. A D′ band, typical of highly oxidized samples was not observed in the test material. EDS spectra indicated that nickel was present in the test material; subsequent NAA quantitated nickel at 0.52% by weight. None of the other elements quantitated by NAA (chlorine, cobalt, iron, and copper) were detected above 0.01%. XPS survey scans detected only carbon and oxygen on the surface of the test material. Subsequent high-resolution scans indicated the surface composition of the bulk chemical was approximately 98 atom % carbon and 2 atom % oxygen, consistent with literature values.^83,84^ BET gas adsorption analysis indicated an average surface area of 175 m^2^/g for lot 10031301M, consistent with values provided by the supplier. Skeletal density, as determined by helium gas pycnometry, was 2.0 g/cm^3^. This result was in good agreement with the density reported by the supplier. Measurement of the electrophoretic velocity of L-MWNT-1020 in distilled water yielded a zeta potential of −30 mV, consistent with published values for similar nanotube materials.^85^

Figure 2

Electron Microscopy Images of 1020 Long Multiwalled Carbon Nanotubes

A) Transmission electron microscopy of bulk L-MWNT-1020; B) higher resolution transmission electron microscopy of bulk L-MWNT-1020; C) scanning electron microscopy of dispersed L-MWNT-1020 for length analysis.

The purity of lot 10031301M was determined by Galbraith Laboratories, Inc. (Knoxville, TN) using elemental analysis and by Netzsch Instruments (Burlington, MA) using thermogravimetric analysis (TGA). Elemental analysis for carbon, hydrogen, nitrogen, and sulfur indicated that lot 10031301M was 97% carbon by weight and the other elements assayed were below the quantitation limits of the method used (<0.5%). TGA estimated the average percent purity of L-MWNT-1020 as approximately 99% for all containers received. The overall purity of lot 10031301M was determined to be 97% or greater.

To ensure stability, the bulk test material was stored in the original 12 amber glass shipping jars at room temperature. Periodic reanalyses of the test material were performed by the study laboratory with TGA and Raman spectroscopy, and no degradation of the bulk test material was detected.

## Aerosol Generation and Exposure System

The aerosol generation system consisted of a linear feed dust metering device to meter L-MWNT-1020 from a reservoir into an air stream. Within the metering device, periodic blasts of compressed air suspended small volumes of test material in the air stream for transport to the metering device exhaust tube. A particle attrition chamber was positioned immediately downstream of the metering device exhaust tube for initial particle size reduction of the test material. From the particle attrition chamber, the aerosol was passed through a single jet disperser into the distribution line. The single jet disperser assisted in further dispersion and particle size reduction. Downstream of the disperser jet, primary dilution air (filtered, compressed, humidified air) was added to increase the volumetric flow rate in the aerosol distribution line before the aerosol was passed through a cyclone separator. The cyclone separator removed the larger particles from the distribution system. The linear feed dust metering device, single jet disperser, the primary dilution air assembly and the cyclone separator were housed within a glove box located within the exposure control suite. Secondary dilution air (filtered, compressed, humidified air) was added outside of the glove box within the exposure control suite.

Within the distribution line, aerosol was conveyed from the exposure control suite to the exposure room. In the exposure room, the distribution line split into two lines for delivery to chambers situated on both sides of the exposure room. One branch transported aerosol to the 0.3, 1, and 3 mg/m^3^ chambers, and the second branch transported aerosol to the 0.1 and 10 mg/m^3^ chambers. During exposures, the air flow through the distribution lines was controlled using house vacuum regulated by a filter-protected flow meter. A second distribution line flow control system was available during off-exposure periods. This system consisted of a vacuum transducer pump of higher flow capacity positioned in parallel with the flow meter control assembly that became operational only during critical shut-down periods. High-efficiency particulate air (HEPA) filters were placed before the vacuum supply and transducer pump at the end of each delivery line to remove aerosol from the airstream prior to exhausting from the room. At each exposure chamber location, aerosol was directed from the distribution line by a sampling tube into the chamber conditioned air supply for mixing prior to delivery to the chamber. The flow through the sampling tube was induced by a stainless steel ejector pump designed and fabricated at Battelle. The flow rate and configuration of each ejector pump and sampling tube combination were chosen to optimize the efficiency of the delivery system and achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Lab Products, Inc., Seaford, DE) so that uniform aerosol concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. At each exposure concentration, the chambers housed both rats and mice from the concurrent studies.

## Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table D-1. The concentrations of L-MWNT-1020 in the exposure chambers and room air were monitored using three real-time aerosol monitors (RAMs). The monitors were connected to the chambers through sample lines and a multiplexing valve designed to minimize aerosol losses caused by settling or impaction. Each RAM was multiplexed to the exposure chambers and/or the 0 mg/m^3^ chamber or the exposure room and a HEPA-filtered air blank. The output voltage of each RAM was recorded by the Battelle Exposure Data Acquisition and Control software system and converted to mg/m^3^ exposure concentration by the application of a calibration curve. Each measured concentration was compared to limit values for the locations monitored by each RAM and, if a measured concentration exceeded its control limits, the Battelle Exposure Data Acquisition and Control (BEDAC) system triggered an audible alert or, in extreme cases, terminated the exposure.

Each RAM was calibrated by constructing a response curve using the measured RAM voltages (corrected for zero offset voltage measured in a HEPA-filtered airstream) and L-MWNT-1020 concentrations determined by gravimetric analysis of filter samples obtained from the exposure chambers. Duplicate exposure chamber atmosphere samples were collected each day on Teflon^®^-coated, glass fiber filters. Validation studies demonstrated that gravimetric and chemical-specific measurements of chamber concentrations were comparable. An ultraviolet visible spectrophotometric assay was used for chemical-specific analysis of L-MWNT-1020. This assay used an off-line liquid chromatograph to measure changes in absorbance (at 538 nm) of an aqueous solution that contained a dye that had an affinity for filter-trapped L-MWNT-1020. The off-line chromatograph was calibrated using gravimetrically prepared calibration standards of the test article. These methods were demonstrated by the study laboratory to have adequate precision, accuracy, linear working range, day-to-day respectability, and detection limits for the L-MWNT-1020 concentrations in the exposure chambers.

## Chamber Atmosphere Characterization

Aerosol particle size distribution was determined once prior to and once during the 30-day studies by collecting aerosol samples from each exposure chamber using a Mercer-style cascade impactor. L-MWNT-1020 was collected (for stages one through seven) on 37 mm stainless steel slides lightly coated with silicone or (for stage eight) 47 mm Teflon-coated glass fiber filters to establish the mass median aerodynamic diameter (MMAD) of the aerosol particles. The impactor samples were analyzed gravimetrically to determine the amount of L-MWNT-1020 collected on each stage. The relative mass of L-MWNT-1020 collected on each impactor stage was analyzed by the NEWCAS impactor analysis program developed at the study laboratory based on probit analysis.^86^ All MMAD values were below the 3.0 µm upper limit criterion required by the design of the studies.

For each exposure chamber, the count median diameter (CMD) for the aerosol and the number of particles per unit volume were determined once before and once during the 30-day studies using an electrical low pressure impactor (ELPI). The ELPI counted the number of particles in 12 size bins within a size range of 0.03 to 10 µm. The CMD and particle number concentration were analyzed using the ELPI VI 4.0 Data Analysis Software provided by the manufacturer. CMDs for the aerosol ranged from 92 to 99 nm with the number of particles varying from 3.5 × 10^4^ to 1.1 × 10^6^ particles/cm^3^.

Buildup and decay rates for chamber aerosol concentrations were determined at two ports for each chamber with and without animals present in the chambers. At a chamber airflow rate of 15 ft^3^/minute, the theoretical value for the time to achieve 90% of the target concentration after the beginning of aerosol generation (T_90_) was approximately 9.2 minutes and the time for the chamber concentration to decay to 10% of the target concentration after aerosol generation was terminated (T_10_) was approximately 12 minutes. A T_90_ value of 12 minutes was selected for the studies.

The uniformity of aerosol concentration in the inhalation exposure chambers without animals was evaluated before the studies began; in addition, concentration uniformity with animals present in the chamber was measured once during the 30-day studies. Concentrations were measured at all 12 sample ports; one in front and one in back for each of six possible animal cage unit positions per chamber. Chamber concentration uniformity was maintained throughout the studies.

The persistence of L-MWNT-1020 in the chambers after aerosol delivery ended was determined by monitoring the concentration overnight in the 10 mg/m^3^ chamber in the 30-day studies with and without animals present in the chamber. The concentration decreased to 1% of the target concentration within 14 minutes with animals present and within 18 minutes without animals.

Stability studies of L-MWNT-1020 in the generation and delivery system were performed before and during the studies by EMSL/PNNL (TEM, Raman spectroscopy, and XPS), Quantachrome Instruments (BET surface area), Netzsch Instruments (TGA), and the study laboratory (elemental analysis by inductively coupled plasma/atomic emission spectroscopy [ICP/AES]). TEM imagery indicated that the morphology of the test material collected from the exposure aerosol was qualitatively similar to that observed in the bulk material (Figure 3). BET surface area analysis determined that the surface area of the test material in the exposure system was generally comparable to the results of the initial characterization tests of lot 10031301M. Raman spectra of L-MWNT-1020 collected from the exposure system were consistent with Raman spectra of the bulk chemical as determined in the initial test chemical characterization. XPS surface scans of the exposure system aerosol samples indicated that the surface of L-MWNT-1020 included carbon and oxygen and that substantial oxidation of the test chemical did not occur during generation of aerosolized exposure atmospheres. No impurities or degradation products were detected by TGA in any of the exposure atmosphere aerosol samples. ICP/AES results were consistent with elemental analyses of the bulk test material in the initial characterization of the test chemical. Taken together, these results demonstrated that the composition of L-MWNT-1020 was stable in the exposure system and contamination from metal materials in the exposure system did not occur.

Figure 3

Representative Transmission Electron Microscopy from 1020 Long Multiwalled Carbon Nanotubes Chamber Samples

A) 0.1 mg/m^3^ chamber sample; B) 10 mg/m^3^ chamber sample.

## Animal Source

Male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Livermore, CA), and male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained at Taconic Biosciences, Inc. (Germantown, NY), for the 30-day studies.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the AAALAC International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

On receipt, the rats and mice were 4 to 5 weeks old. Animals were quarantined for 12 days and were 5 to 6 weeks old on the first day of the studies. Before the studies began, 5 male and 5 female rats and mice were randomly selected for parasite evaluation (pinworms, Syphacia obvalata and S. muris) and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix F). All test results were negative.

## Lung Burden Studies

For lung burden determination, groups of 25 male and 25 female rats and mice were exposed to L-MWNT-1020 by whole-body inhalation at concentrations of 0, 0.1, 0.3, 1, 3, or 10 mg/m^3^, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 30 (males) or 31 (females) days. These exposure concentrations were selected based on 90-day studies in the literature that reported moderate toxicologic effects following inhalation exposure to up to 6 mg/m^3^ MWCNT.^49,52^ Animals were weighed and lungs were collected from 10 male and 10 female rats and mice on the last exposure day and from 5 male and 5 female rats and mice after 14, 42, and 126 days of recovery. Right and left lung lobes were weighed separately and stored at −70°C until analysis for nickel concentration. Homogenized samples of lung tissue (left and right lobes combined; 2 g for rats and 0.2 g for mice) were weighed into microwave digestion vessels along with 0.2 mL of a 1 mg yttrium/mL internal standard and 10 mL of 70% nitric acid. After a 15-minute predigestion, the samples were digested in a microwave sample preparation system (CEM Corp., Matthews, NC). Samples were diluted to an appropriate volume with deionized water before analysis using inductively coupled plasma-mass spectroscopy (Agilent 7500ce ICP/MS, Agilent Technologies, Palo Alto, CA).

As has been used in other studies,^53,54^ monitoring of the residual metal catalyst was used as a surrogate for measurement of the MWCNT burden. Nickel content, which makes up 0.52% of L-MWNT-1020, was used to determine the amount of L-MWNT-1020 in lung samples. Studies conducted during prestart activities confirmed that nickel remained bound to the L-MWNT-1020 in the exposure atmosphere. These studies were conducted to determine if nickel would leach from the L-MWNT-1020. L-MWNT-1020 samples were prepared in simulated lung fluid (Gamble’s solution), incubated at 37°C, and removed from the incubator at 0, 2, 7, 15, and 29 days following preparation. At each timepoint, the bottles were shaken vigorously, centrifuged, and filtered. Triplicate samples were analyzed for nickel content by ICP/MS. No more than about 1% of nickel present in the L-MWNT-1020 leached out over a period up to 29 days in synthetic lung fluid. This amount is within the margin of error for ICP/AES measurements. In addition to the leaching experiments, the long half-life of nickel in the lungs of exposed animals indicated that it was tightly bound; a much shorter half-life would be expected if nickel was mobilized from the nanotubes.

Lung nickel concentration (μg Ni/g lung) was calculated by multiplying the internal standard corrected nickel concentration (μg Ni/L) measured in the digest by the nominal dilution volume (L) and dividing by the sample weight (g). Mean recoveries of nickel from spiked rat lung (1.0 ± 0.04 g) ranged from 16% to 32% with relative standard deviations (RSDs) ranging from 13% to 63%. To evaluate the effects of interference arising from the lung matrix, a spiked rat standard using two times the mass of lung tissue (~2 g) was assayed. The spiked rat lung had a mean recovery of 34% with an RSD of 16%. Mean recoveries from spiked mouse lung (0.12 ± 0.04 g) ranged from 25% to 82% with RSDs ranging from 6% to 40%. The mean recovery from the spiked mouse standard—using two times the mass of lung tissue (~0.24 g) to evaluate the effects of interference arising from the lung matrix—was 36% with an RSD of 3%.

Total lung burden (μg Ni/lung) was calculated by multiplying the measured nickel concentration (μg Ni/g) by the total sample weight at collection (g). Total lung L-MWNT-1020 burden (μg L-MWNT-1020/lung) was calculated by dividing the total lung burden (μg Ni/lung) by the fraction of nickel in L-MWNT-1020 (0.52%). Total L-MWNT-1020 burdens normalized to exposure concentration (μg L-MWNT-1020/lung per mg L-MWNT-1020/m^3^) were calculated by dividing the total lung L-MWNT-1020 burden by the corresponding target exposure concentration (mg/m^3^).

Lung clearance rates for L-MWNT-1020 were calculated using Equation (1):

Equation (1): A(t) = A_0_(e^−kt^)

where A(t) is the lung burden (µg L-MWNT-1020/lung) at time t (days postexposure), A_0_ is the lung burden at t = 0 days postexposure (day 30 [males] or 31 [females]), and k is the lung clearance rate constant (fraction cleared per day). Using this model, the data were plotted on a semilog scale and Equation (1) fitted to the plot using a least-squares error minimization curve fitting method with weighting (lung burden)^−1^. This fit produced estimates of A_0_ and k as well as standard deviations for each estimate. Using this model, a semilog plot of A(t) versus time produces a straight line with y-intercept A_0_ and slope −k.

Lung clearance half-lives in days (t_½_) were calculated from Equation (2):

Equation (2): t_½_ = ln2/k

Standard deviations for calculated half-lives were estimated using the uncertainty in k determined by the model fit.

## Core Studies

For the core studies, groups of 10 male and 10 female rats and mice were exposed to the same concentrations of L-MWNT-1020 for the same length of time as in the lung burden study. Feed and water were available ad libitum, except feed was withheld during exposure periods. Animals were randomized into groups and assigned identification numbers based on body weights. Rats and mice were housed individually in stainless steel wire-bottom cages within each exposure chamber. Cage units were rotated among levels in each chamber during weekly chamber change-out. Rotation consisted of moving each cage unit to the next lower occupied level and moving the bottom unit to the highest occupied level of the chamber. Body weights were recorded on day 1, and clinical observations and body weights were recorded on day 9, weekly thereafter, and at the end of the studies. Necropsies were performed on all core study rats and mice. Details of the study design, animal maintenance, and tissues and organs examined are summarized in Table 1. Organs weighed at necropsy included the liver, thymus, right kidney, right testis, heart, and lungs. For histopathology, protocol required tissues included nasal cavity, trachea, larynx, pharynx, lymph nodes (mediastinal and bronchial), lungs (with mainstem bronchi), and gross lesions (as applicable). Tissues were fixed in 10% neutral buffered formalin. Testes, vaginal tunics, and epididymides were fixed in modified Davidson’s and then transferred to 10% neutral buffered formalin. Tissues were trimmed, processed, embedded in paraffin, sectioned, and stained with hematoxylin and eosin (H&E). Histopathologic evaluation was limited to gross lesions and the following tissues: larynx, lungs and mainstem bronchi, lymph nodes (bronchial and mediastinal), nose, pharynx, and trachea. Microscopic examinations of these tissues were performed on control animals and those exposed to 10 mg/m^3^. Exposure-related lesions were examined to a no-effect level. Gross lesions from all exposure groups were also examined microscopically.

Table 1 Experimental Design and Materials and Methods in the 30-day Inhalation Studies of 1020 Long Multiwalled Carbon Nanotubes

Thirty-day Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats
B6C3F1/N mice
Animal Source
Rats: Envigo (formerly Harlan Laboratories, Inc., Livermore, CA) Mice: Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
12 days
Average Age When Studies Began
Rats: 6 weeks Mice: 5 to 6 weeks
Date of First Exposure
Rats: May 23, 2011 Mice: May 30, 2011
Duration of Exposure
6 hours plus T90 (12 minutes) per day, 5 days per week, for 30 (males) or 31 (females) days
Date of Last Exposure
Rats: June 21 (males) or June 22 (females), 2011 Mice: June 28 (males) or June 29 (females), 2011
Necropsy Dates
Rats: June 22 (males) or June 23 (females), 2011 Mice: June 29 (males) or June 30 (females), 2011
Average Age at Necropsy
10 to 11 weeks
Size of Study Groups
Lung burden study: 25 males and 25 females Core study: 10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 open formula pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum except during exposure periods, changed daily
Water
Tap water (Richland municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum
Cages
Stainless steel wire bottom (Lab Products, Inc., Seaford, DE), changed and rotated weekly
Cageboard Untreated paper cage pan liner (Techboard Ultra, Shepherd Specialty Papers, Watertown, TN), changed daily
Chamber Air Supply Filters
Single HEPA (open stock), charcoal (RSE, Inc., New Baltimore, MI), Purafil (Environmental Systems, Lynnwood, WA), all new at study start
Chambers
Stainless steel excreta pan at each of six levels (Lab Products, Inc., Seaford, DE), chamber changed weekly, excreta pan changed daily
Chamber Environment
Temperature: 72°F ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: at least 15/hour
Exposure Concentrations
0, 0.1, 0.3, 1, 3 or 10 mg/m^3^
Type and Frequency of Observation
Observed twice daily; core study animals were weighed initially, on day 9, then weekly and at the end of the studies; clinical observations were recorded on day 9, then weekly and at the end of the studies.
Method of Euthanasia
Carbon dioxide inhalation
Lung Burden Studies
Postexposure on the last exposure day (10 male and 10 female rats and mice) and after 14, 42, and 126 days of recovery (5 male and 5 female rats and mice per timepoint) lung burden animals were weighed and lungs were collected, weighed, and analyzed for nickel concentration, which was used to calculate L-MWNT-1020 concentration.
Necropsy
Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Histopathology
Histopathology was performed on all core study rats and mice. Histopathologic evaluation was limited to gross lesions and the following tissues: larynx, lungs and mainstem bronchi, lymph nodes (bronchial and mediastinal), nose, pharynx, and trachea.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to an NTP Pathology Peer Review (PPR) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP PPR process. Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PPR coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^87^ and Boorman et al.^88^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^89^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^90^ and Williams.^91,92^ Lung burden data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^93^ (as modified by Williams^94^) and Dunn.^95^ Jonckheere’s test^96^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^97^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

The 30-day studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^98^ In addition, as records from the 30-day studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Report.