# Introduction

Figure 1

Multiwall Carbon Nanotube Structure

## Chemical and Physical Properties

Carbon nanotubes (CNT) are highly ordered hexagonal lattices of carbon atoms arranged into cylinders by hydrogen bonding, dipolar forces, hydrophilic or hydrophobic interactions, gravity, and other forces.^1^ A single-wall carbon nanotube (SWCNT) has been described as a single sheet of graphene rolled to form a seamless nanoscale cylinder.^2^ Multiwalled carbon nanotubes (MWCNTs), such as 1020 Long Multiwalled Carbon Nanotube (L-MWNT-1020), consist of many SWCNTs, one inside of another, and held together by van der Waals bonding. MWCNTs exhibit superior mechanical, chemical, electronic, and optical properties and are highly stable and chemically unreactive. MWCNTs are thermally stable up to 2800°C in vacuum; thermal conductivity is approximately twice that of diamond, and electric current carrying capacity is 1,000 times higher than copper wires.^3^

The chemical and physical characteristics of MWCNTs vary significantly depending on the production method and postsynthesis processing. Unpurified MWCNTs typically contain amorphous carbon contaminants, SWCNTs, and residual metal catalysts. Metal catalysts such as iron and nickel can be present at 30% or greater by mass.^4^ MWCNT may also be contaminated with magnesium oxides, aluminates, and silicates that are often used to support the catalyst or growth region.^2^ Although MWCNTs are generally purified to remove these contaminants, varying amounts remain in the final material. Purification procedures can also add additional contaminants such as carboxylic acid residues.^2^ The ability to functionalize MWCNTs by the addition of specific functional groups to the carbon lattice can result in significant changes in the chemical and physical properties. Functionalization has been used to optimize solubility, dispersion, conductivity, and other properties of the MWCNT^5^ resulting in a wide array of applications.

The physical dimensions of MWCNTs depend on the synthesis method. The diameters of MWCNTs depend on the number of encapsulated tubes and can range from 10 to 100 nm.^6^ The lengths of MWCNTs are generally dependent on synthesis time and can be tens of micrometers long.^7^ Some MWCNT can assemble into low-density agglomerates of intertwined and entangled tubules due to the attraction of van der Waals forces. The structure and size of these agglomerates is determined primarily by the dimensions of the MWCNT. Flexible, thin-walled MWCNTs more readily assemble into agglomerates than rigid, thick-walled MWCNTs.

## Production, Use, and Human Exposure

MWCNTs are synthesized by applying energy to a carbon source producing individual or groups of carbon atoms that reassemble into tubes. Common methods of synthesis include chemical vapor deposition, laser ablation, arc discharge, and high-pressure carbon monoxide conversion. A metal catalyst (e.g., cobalt, iron, nickel, or molybdenum) is often used to reduce the synthesis temperature and increase the yield and homogeneity. Chemical vapor deposition is the primary method used for high volume production of MWCNTs.^8^ MWCNTs also can occur as a by-product of natural events, such as forest fires,^9^ and industrial processes, such as combustion of propane and natural gas.^10^

More efficient and less costly production methods have resulted in large-scale production of CNTs with annual production capacities of some grades reaching thousands of tons.^11^ With the commercial availability of bulk quantities of CNTs, there are increasing numbers of industries to explore new commercial opportunities. The global production of MWCNTs and SWCNTs increased more than 10-fold between 2006 and 2012.^8^ MWCNTs are produced in far greater numbers than are SWCNTs^12^ because of their lower production cost and because their use in composite materials requires greater volume. In 2014, worldwide commercial MWCNT production commitment (Tier 1 companies) was 1,445 tons and was predicted to reach 4,195 tons by 2019.^11^

One of the largest uses of MWCNTs is in nanotube-reinforced polymer composite materials.^8^ The exceptional mechanical properties and low density of MWCNTs make them ideal for application to products requiring load-bearing strength and durability. MWCNT powders are mixed with polymers or resins to improve stiffness, strength, and toughness.^13^ The MWCNT-composite market has the potential to expand significantly as methods improve and more applications are discovered. Other commercial applications for MWCNT include use in batteries, automotive parts, sporting goods, boat hulls, water filters, thin-film electronics, coatings, actuators, and electromagnetic fields.^8^ Functionalized MWCNTs have been investigated for potential use as nanocarriers for targeted drug or biomolecule delivery because of their small size, high loading capacity, and functional surface chemistry.^14^ Functionalized MWCNTs show great promise in biomedical applications, such as gene/drug delivery, bacterial filters, molecular diagnoses, cancer and infection treatments, and bone tissue engineering.^15-21^

Human exposure to MWCNTs occurs primarily in the workplace. Because MWCNT production and use are relatively recent and numbers of potentially exposed workers are small, only limited occupational exposure data are available. A number of studies, including some sponsored by NTP, demonstrated the potential of occupational exposure to MWCNT.^22-32^ Most of these studies were conducted in small research and development facilities where only small amounts of MWCNTs are synthesized and handled. Worker exposure to MWCNT can occur during the transfer, weighing, blending, and mixing of the bulk powders, and during the machining of MWCNT-composite materials.^33^ Low levels of exposure can occur during disposal and recycling of materials containing MWCNT.^34^ In general, these studies provide evidence that exposure of workers to MWCNT can occur, especially where exposure control measures have not been implemented. However, assessment of exposure concentrations is difficult due to the limited amount of exposure data, the lack of specific and sensitive methods for analyzing MWCNT, and the heterogeneity of exposure conditions.

## Regulatory Status

The Occupational Safety and Health Administration^35^ recommended that worker exposure to respirable carbon nanotubes and carbon nanofibers not exceed 1.0 μg/m^3^ as an 8-hour time-weighted average in accordance with the National Institute for Occupational Safety and Health (NIOSH) proposed recommended exposure limit (REL). The NIOSH REL was derived using published subchronic and short-term animal studies with dose-response data of early stage fibrotic and inflammatory lung responses to CNT exposure.^36^

## Toxicokinetics

Studies of MWCNT pharmacokinetics in humans were not found in the literature. Only limited animal data were available and were difficult to evaluate due to the heterogeneity of MWCNT studied and methodological differences. Pharmacokinetic studies of MWCNTs in animals have focused on systemic exposure following oral or intravenous administration of functionalized CNTs, primarily SWCNTs. Toxicokinetic studies of MWCNTs in animals have focused on pulmonary exposure because this is the most relevant for human exposure. In the majority of these studies, MWCNTs were administered by intratracheal instillation (rats) or oropharyngeal aspiration (mice). These nonphysiological routes of administration entail a single bolus dose of MWCNTs suspended in liquid media. The toxicokinetics and fate of particles administered by these routes are different than those following inhalation.^37,38^

Because purified (synthetic biproducts removed) MWCNTs are highly stable and chemically unreactive, absorption and metabolism in the body are not major concerns. The primary toxicokinetic considerations for MWCNTs are distribution and clearance in the respiratory tract. Inhalation exposure to MWCNTs is a major concern because of the small respirable size and limited solubility. Single MWCNTs or agglomerates with mass median aerodynamic diameters (MMAD) of less than about 5 µm can be distributed throughout the human respiratory tract, including the alveoli, whereas larger particles are deposited in the nose and upper airways. Micrometer-sized particulate matter in the alveoli is cleared following phagocytosis by alveolar macrophages and then transported via the mucociliary escalator to the gastrointestinal tract or by translocation to the draining lung-associated lymph nodes.^39^ Several studies have reported the presence of MWCNT in subpleural tissues following inhalation exposure.^40-42^

Poorly soluble particles with a high aspect ratio like MWCNTs are not easily phagocytized and are cleared slowly by alveolar macrophages.^43,44^ Failure to fully phagocytize long MWCNT (e.g., in which the MWCNT length is greater than macrophage diameter) can result in release of degradative lysosomal enzymes into the interstitium causing damage to nearby cells.^45,46^ Macrophage function and clearance also can become impaired when ingested particles occupy more than 6% of the macrophage volume.^47,48^ When MWCNT deposition exceeds clearance, the lung burden increases and results in lung overload and toxicity.

The kinetics of MWCNTs in the lung and lung-associated lymph nodes of male Wistar rats were investigated during a nose-only inhalation exposure to MWCNT.^49^ Animals (six per group) were exposed 6 hours per day, 5 days per week for 13 consecutive weeks to 0, 0.1, 0.4, 1.5, or 6 mg/m^3^ MWCNT (Baytubes^®^; Bayer MaterialScience, Leverkusen, Germany). Individual MWCNT contained 0.115% cobalt and were approximately 10 nm in diameter and 200 to 300 nm in length; however, MWCNT dispersed into the inhalation chambers were primarily agglomerates of tangled and intertwined MWCNT that were 2 to 3 µM in diameter. The left lung and lung-associated lymph nodes were collected and analyzed for cobalt as a marker of exposure during weeks 8, 13, 17, 26, and 39. Minimal to moderate lung overload occurred in the animals exposed to 0.1 and 0.4 mg/m^3^, whereas impaired clearance to complete stasis appeared to occur at 1.5 and 6 mg/m^3^. A time- and concentration-dependent increase of cobalt in the lung-associated lymph nodes occurred at 1.5 and 6 mg/m^3^ during the postexposure period (weeks 17, 26, and 39).^49^

In another study, male C57Bl/6 mice were exposed by inhalation to 5 mg/m^3^ MWCNT-7 (Mitsui-7; Hodogaya Chemical Company, Ltd., Tokyo, Japan).^41^ MWCNT-7 carbon nanotubes are relatively short (1 to 19 μm), thick (40 to 170 nm) and rigid. Mice were exposed 5 hours per day, 4 days per week for 3 weeks, and the MWCNT distribution and lung burden were evaluated at 1, 14, 28, 84, 168, and 336 days postexposure.^41^ Initially, 84% of the MWCNT were in the alveolar region (including 1.2% in the subpleural region) and 16% in the airways. At 336 days postexposure, 95.8% of the initial lung burden remained in the alveolar region (including 4.8% in subpleural region) and 4.2% were found in the airways. Burden in the airways decreased rapidly postexposure and reached a steady state by 14 days postexposure. Initially, most of the MWCNT in the alveolar region were present in alveolar macrophages. Clearance occurred most rapidly in the alveolar macrophage fraction followed by the alveolar tissue. Overall, MWCNT lung burden decreased with postexposure time. Agglomerates of MWCNT (greater than four MWCNT per agglomerate) accounted for the majority of MWCNT cleared from the lung, whereas the burden present as single MWCNT remained unchanged.^41^

## Toxicity

The toxic properties of MWCNTs are dependent on their functionalization, dispersibility and aggregation, biopersistence, route of exposure, and dose. Concerns for the toxicity of MWCNTs are because of their submicron size, their fiber-like geometry, and biopersistence.^50^

### Experimental Animals

Although inhalation is the most relevant route of human exposure to MWCNTs, few subchronic inhalation studies have been conducted in laboratory animals. Mitchell et al.^51^ conducted inhalation studies in C57Bl/6 mice at low exposure concentrations (0.3 to 5 mg/m^3^) of respirable MWCNT 6 hours per day for up to 2 weeks. MWCNTs (Shenzhen Nanotech Port Company, Shenzhen, China) were about 10 to 20 nm in diameter and 5 to 15 µm in length and existed primarily as aggregates less than 1 µm diameter. MWCNT exposure did not cause inflammation or histopathologic lesions in the lungs; however, a systemic immunosuppression was observed in mice at all exposure concentrations when evaluated at 14 days. Immunosuppression was not exposure concentration-related and was characterized by a reduced T-cell dependent antibody response to sheep red blood cells and a reduced T-cell proliferative capacity in response to the mitogen Concanavalin A.

A single 6-hour exposure of C57Bl/6 mice to 30 mg/m^3^ of MWCNT (Helix Material Solutions, Richardson, TX; length of 0.5 to 50 µm; MMAD of 0.183 µm) resulted in a clear increase in subpleural fibrosis at 2 and 6 weeks postexposure.^40^ MWCNT were observed within alveolar macrophages, subpleural mesenchymal cells, and the subpleural collagen matrix. Mononuclear cell aggregates containing macrophages with engulfed MWCNT were present on the pleural surface of mice exposed to 30 mg/m^3^ when evaluated 1 day and 2 weeks postexposure.

Wistar Han rats were exposed to MWCNT (Nanocyl^®^ NC 7000^TM^, Sambreville, Belgium) aerosols 6 hours per day, 5 days per week for 13 weeks at concentrations of 0.1, 0.5, or 2.5 mg/m^3^.^52^ Examination of the test atmospheres revealed that animals were exposed to agglomerates ranging from 0.7 to 2.0 µm MMAD. Treatment-related lesions were present in the nasal cavity, larynx, trachea, lungs, and mediastinal lymph nodes. Except for a slight neutropenia at 2.5 mg/m^3^, there was no evidence of extrapulmonary toxicity. Increased lung weights, multifocal granulomatous inflammation, diffuse histiocytic and neutrophilic inflammation, and intra-alveolar lipoproteinosis were observed in the lung and lung-associated lymph nodes at 0.5 and 2.5 mg/m^3^. The incidence and severity of these effects were related to exposure concentration.

Ellinger-Ziegelbauer^53^ and Pauluhn^54^ compared the pulmonary toxicity of Baytubes (Bayer MaterialScience, Leverkusen, Germany) containing 0.53% cobalt and metal-depleted Baytubes containing 0.12% cobalt. Baytubes are a thin-walled MWCNT with a mean diameter of 10 to 16 nm and a mean length of 200 to 300 nm, and form coiled tangled agglomerates. Baytubes were micronized to a respirable size (2 to 3 µm MMAD) prior to use. α-Quartz (2.3 µm MMAD) was used as a reference dust for particle-induced toxicity. Male Wistar rats were exposed to either air, Baytubes (11 or 241 mg/m^3^), depleted Baytubes (11 mg/m^3^), or α-quartz (248 mg/m^3^) for 6 hours by nose-only inhalation followed by a 3-month postexposure period. Baytubes caused concentration-dependent pulmonary inflammation that decreased with time after exposure. Inflammation was characterized by increased bronchoalveolar lavage fluid (BALF) cellularity, lactate dehydrogenase (LDH) activity, protein, and collagen, enlarged and/or foamy macrophages, and upregulation of lung inflammatory cytokines and chemokines. The time-course of inflammation was the same for Baytubes and metal-depleted Baytubes; α-quartz caused more progressive inflammatory changes over time. The authors concluded that the pulmonary inflammatory response to MWCNT is primarily dependent on the assemblage structure and not metal impurities.

In a subsequent study, Pauluhn^49^ investigated the inhalation toxicity and lung clearance of Baytubes in male and female Wistar Han rats following nose-only inhalation exposure to 0, 0.1, 0.4, 1.5 or 6 mg/m^3^ 6 hours per day, 5 days per week, for 13 weeks. Lung and lung-associated lymph node weights were increased in rats exposed to 0.4 mg/m^3^ or greater. Exposure-related histopathologic lesions were present in the nasal cavity, lung, and lung-associated lymph nodes of rats exposed to 0.4 mg/m^3^ or greater. No lesions were found in extrapulmonary tissues. Lung burden data indicated that minimal to moderate lung overload occurred at 0.1 and 0.4 mg/m^3^, whereas impaired clearance to complete stasis may have occurred at 1.5 and 6 mg/m^3^.

The pulmonary inflammation and genotoxicity of Graphistrength^©^ C100 MWCNT (Arkema, Colombes, France) was investigated in a 90-day nose-only inhalation study in male and female Wistar rats.^55^ Graphistrength^©^ C100 consists of large agglomerates of entangled MWCNT and was micronized prior to use to provide respirable-size particles (mean diameter of 11 to 12 nm; mean length of approximately 1 µm; MMAD of 1.6 to 2.3 µm). Rats were exposed to 0, 0.05, 0.25, or 5 mg/m^3^ for 90 days followed by a 90-day recovery period. Twenty-four hours and 90 days after the 90-day exposure, 10 rats per sex per concentration were sacrificed for BALF measurements (left lung only) and histopathology. Numbers of macrophages decreased and neutrophil numbers increased in BALF at 24 hours after exposure to 0.25 and 5 mg/m^3^, and at 90 days postexposure to 5 mg/m^3^. BALF levels of phospholipids, LDH, alkaline phosphatase, gamma-glutamyl transferase, and protein were elevated at 24 hours and 90 days postexposure in rats exposed to 5 mg/m^3^. A prolonged release of TNF-α in BALF was observed at 0.25 and 5 mg/m^3^. An increase in interstitial collagen staining was observed at 5 mg/m^3^, similar to that reported following exposure of rats to Baytube^®^ MWCNT.^49^ Other histopathologic changes noted at 90 days postexposure were eosinophilic inclusions in respiratory and olfactory epithelium in the nose, minimal squamous metaplasia in the larynx, and increased lymphocytes in the tracheobronchial lymph nodes. No pleural effects were observed. After 90 days of recovery, clearance of MWCNT particles was observed in the 0.5 and 0.25 mg/m^3^ groups; however, particle clearance was unchanged at 90 days postexposure in the 5 mg/m^3^ group, indicating an inhibition of clearance and lung overload. No exposure-related effects were observed on sperm counts, motility, and morphology 24 hours and 90 days postexposure. The results of genotoxicity assays (micronucleus test and comet assay) are discussed below.

A number of inhalation studies^41,42,56^ have been conducted on MWCNT-7 (Mitsui-7, Hodogaya Chemical Company, Ltd.). MWCNT-7 carbon nanotubes are relatively short (1 to 19 μm) and thick (40 to 170 nm) with structures that range from single nanotubes to agglomerates with a MMAD of 1.5 µm. Because of their fiber-like dimensions and rigidity, many studies have examined the ability of MWCNT-7 to penetrate the pleural wall and cause pulmonary toxicity and mesothelioma.

Porter et al.^42^ investigated the acute pulmonary toxicity of MWCNT-7 in male C57Bl/6 mice after exposure to 10 mg/m^3^ MWCNT-7 for 5 hours per day for 2, 4, 8, or 12 days. MWCNT-7 lung burden was linearly related to exposure concentration. MWCNT-7 were most frequently deposited in the bronchioles and proximal alveolar regions of exposed mice and at the pleural wall in two exposed mice. Exposure concentration-dependent increases in lung inflammation and cytotoxicity were indicated on day 1 by increases in BALF neutrophils and LDH levels. Histopathologic lesions in lungs of exposed mice included bronchiolocentric inflammation, bronchiolar epithelial cell hyperplasia and hypertrophy, minimal to mild fibrosis, vascular changes, and pleural penetration by MWCNT-7 in two mice.

A 13-week inhalation study of MWCNT-7 was conducted in male and female Fischer 344 rats.^56^ Rats were exposed to 0.2, 1.0, or 5 mg/m^3^ MWCNT-7 for 6 hours per day, 5 days per week for 13 weeks. Lung weights were increased 1.2-fold at 1 mg/m^3^ and 1.3-fold at 5 mg/m^3^ in male and female rats relative to controls. Inflammatory cytokines were increased in the BALF in an exposure concentration-dependent manner beginning at 2 mg/m^3^. Granulomatous changes were present in the lungs of male rats at all exposure concentrations and in females at 1 and 5 mg/m^3^. Focal fibrosis of the alveolar wall was present in both sexes exposed to 1 mg/m^3^ and higher. Inflammatory infiltration of the visceral pleura and subpleural areas was observed in the 5 mg/m^3^ exposure group.

Mercer et al.^41^ investigated the distribution and fibrotic response following whole-body exposure of male C57Bl/6J mice to 5 mg/m^3^ MWCNT-7 for 5 hours per day for 12 days with necropsies at 1, 14, 84, 168, or 336 days postexposure. Pulmonary inflammation, characterized by increases in BALF neutrophils, LDH, and albumin peaked at postexposure day 1 and declined thereafter. Deposition of fibrillar collagen in the alveolar septa progressively increased over the 336 days postexposure. When examined at postexposure day 1, 84% of the MWCNT-7 lung burden was in the alveolar region. Approximately 56% of the alveolar lung burden was in the alveolar macrophages, 7% in the alveolar spaces, and 20% in the alveolar tissue. By postexposure day 168 the macrophage burden had decreased by 35%, whereas the alveolar tissue burden had increased by 63%. Large aggregates of greater than four fibers accounted for most of the cleared MWCNT-7. The amount of single fibers in the alveolar region remained unchanged and was reportedly responsible for the progressive fibrosis up to 336 days postexposure.

A number of MWCNT toxicity studies have been conducted in which MWCNT were administered to the lungs of laboratory animals by intratracheal instillation or oropharyngeal aspiration. Although these studies provide some information on potential mechanisms, the nonphysiological administration of a bolus dose of MWCNT suspended in a dispersion medium makes these studies difficult to interpret with respect to toxicity following inhalation exposure. Administration of MWCNT by these routes often results in greater lung inflammation, granulomas, and fibrosis than would occur following inhalation.^57-60^ In addition, a large number of in vitro studies of MWCNT have been reported. In vitro studies have provided important information on MWCNT solubility and durability, cell surface interactions, and toxicity of metal impurities. However, in vitro toxicity studies have produced a wide spectrum of results due to different MWCNT tested, differences in MWCNT preparation, high doses, cell types used, and a wide variety of test methods.^61^

### Humans

Few studies have evaluated the potential toxicity of MWCNT in humans in part because of low numbers of exposed workers and methodologic limitations. A small cross-sectional study recently was conducted at a large-scale MWCNT manufacturing plant with relatively high occupational exposures to evaluate potential biomarkers of exposure.^62^ Personal breathing zone samples were collected from specific workplaces and analyzed for elemental carbon and particle analysis by transmission electron microscopy. Nasal lavage fluid, induced sputum, and serum were collected from exposed and nonexposed workers and analyzed for biomarkers of inflammation and fibrosis. Blood was collected for measurement of global messenger ribonucleic acid (mRNA) and noncoding RNA (ncRNA) expression. Significant increases were detected in interleukin-1β, interleukin-6, tumor necrosis factor-α, inflammatory cytokines, and Kerbs von Lungren-6, a serologic marker for interstitial lung disease in induced sputum. Transforming growth factor-β, a profibrotic cytokine, was increased in the serum of exposed workers. Significant changes in the mRNA and ncRNA expression profiles were detected in the blood of exposed workers.^63^ A set of microRNAs with roles in cell cycle regulation/progression/control, apoptosis and proliferation were identified. Particle morphology was identified as agglomerates ranging from 0.5 to 10 µm in diameter; individual nanotubes were not observed. The individual time-weighted average concentration of respirable elemental carbon (not specific for MWCNT) was as high as 2.8 mg/m^3^, nearly three times the NIOSH REL, indicating a potential health risk at this exposure concentration particularly with extended exposures.

An exposure assessment conducted at CNT manufacturing plants also evaluated several health endpoints in exposed workers. Lee et al.^64^ examined nine manufacturing workers and four office workers at a large-scale manufacturing facility which produced MWCNT. Exhaled breath condensate (EBC) was used to monitor the potential effects of MWCNT exposures on inflammatory and oxidative stress in the respiratory tract. Particle sizes ranged from approximately 8 to 300 nm in diameter (lengths were not reported). The respirable particle concentrations were estimated to be 1.6 to 2.3 mg/m^3^. The pulmonary function tests and hematology and serum chemistry values in both office and manufacturing workers were reported to be in the normal ranges. Some EBC biomarkers of oxidative stress (i.e., malondialdehyde, 4-hydroxy-2-hexanal, and n-hexanal) were significantly higher in the manufacturing workers. Levels of molybdenum were measured in the blood of workers because molybdenum was used as a catalyst in MWCNT manufacturing. Blood molybdenum levels were increased nonsignificantly in the manufacturing workers and were correlated positively with the EBC oxidative markers malondialdehyde and n-hexanol.

## Reproductive and Developmental Toxicity

No reproductive or developmental toxicity studies in experimental animals or case studies in humans were found in the literature.

## Carcinogenicity

### Experimental Animals

Currently, only one chronic inhalation study in laboratory animals has been conducted to evaluate the potential carcinogenicity of MWCNT.^65^ Groups of 50 6-week old F344/DuCrlCrlj rats of each sex were exposed to MWCNT-7 aerosol for 104 weeks (6 hours per day, 5 days per week) at concentrations of 0, 0.02, 0.2, or 2 mg/m^3^. Samples collected from the inhalation chambers had an average width of 92.9 to 98.2 nm and length of 5.4 to 5.9 µm. Most MWCNT-7 fibers collected from the chambers were single straight fibers and were not aggregated. MWCNT-7 exposure had no significant effect on survival, body weights, or urinary, hematologic, and blood biochemical analyses relative to chamber controls. The incidences of bronchoalveolar carcinomas, total carcinomas (bronchoalveolar carcinoma, adenosquamous carcinoma, adenocarcinoma, and squamous carcinoma) and total carcinomas and/or adenomas in males exposed to 0.2 or 2 mg/m^3^ and in females exposed to 2 mg/m^3^ were increased compared with their respective chamber control groups. Incidences of preneoplastic lesions (bronchoalveolar epithelial hyperplasia and atypical epithelial hyperplasia) were increased in the lungs of male and female rats in an exposure concentration-dependent manner. MWCNT-7 lung burden was determined for rats that were euthanized or died before the end of the 104-week study. The numbers of MWCNT-7 nanotubes in the lungs increased linearly with exposure concentration in males and females. The numbers of nanotubes per body weight were similar for males and females in the different exposed groups.

A two-stage initiation/promotion study was conducted to determine if inhaled MWCNT-7 can act as a complete carcinogen and/or promote the growth of cells with existing DNA damage.^66^ Two groups of B6C3F1 mice were exposed to 5 mg/m^3^ MWCNT-7 or air, 5 hours per day, 5 days per week, for 15 days. Prior to MWCNT-7 exposure, half of the mice were treated with the 3-methylcholanthrene, a known tumor initiator. When examined 17 months postexposure, bronchoalveolar adenomas and adenocarcinomas were observed in 90.5% of the mice in the 3-methylcholanthrene/MWCNT-7 group, 51.9% of 3-methylcholanthrene-only group, 26.5% of the MWCNT-7-only group, and 23% of the untreated chamber control group. Although these results do not indicate that MWCNT-7 alone can cause cancer, exposure to MWCNT-7 may increase the risk of cancer in mice exposed to a known carcinogen.

The fiber-like geometry and biopersistence of MWCNT has resulted in concern that MWCNT may cause mesothelioma similar to that caused by asbestos fibers.^2,36^ Consequently, many studies have been conducted to evaluate the potential of MWCNT to cause mesothelioma following injection into the peritoneal cavity (intraperitoneal injection) in animals. On the basis of the results of these studies, the International Agency for Research on Cancer (IARC) concluded that there was sufficient evidence of carcinogenicity in humans for MWCNT-7, and limited evidence for two other types of MWCNT with dimensions similar to MWCNT-7.^67^ MWCNT-7 caused peritoneal mesotheliomas in male and female rats in one intraperitoneal injection study and one intrascrotal injection study,^68^ and in male p53+/− heterozygous mice in two intraperitoneal injection studies.^69,70^ Two other types of MWCNT with physical dimensions similar to those of MWCNT-7 (1 to 19 μm long by 40 to 170 nm wide) caused mesotheliomas in male and female rats following intraperitoneal injection.^71^ Although intraperitoneal injection is an accepted model for mesothelioma screening, this model does not replicate the toxicokinetics of inhaled MWCNT.

Rittinghausen et al.^72^ also used the intraperitoneal injection model to investigate whether four tailor-made MWCNT of different lengths, diameters, and curvatures could induce mesotheliomas similarly to asbestos fibers. Male Wistar Han (Crl:WI Han) rats (50 per group) received a single intraperitoneal injection of vehicle or one of four MWCNT at either 1 × 10^9^ or 5 × 10^9^ fibers per animal. MWCNT A and B (dimensions of 8.57 µm long by 85 µm wide, and 9.30 µm long by 62 µm wide, respectively) were of medium length with slightly larger diameters than MWCNT C and D. MWCNT C was a long thin fiber (10.24 µm long by 40 nm wide). MWCNT D was a thin fiber of medium length (7.91 µm long by 37 nm wide). A positive control group received an intraperitoneal injection of 1 × 10^8^ long amosite asbestos fibers. Rats were held for 24 months following treatment, and then complete necropsies and histopathologic evaluations were performed. All four MWCNT in all dosed groups caused malignant mesotheliomas. Mesothelioma was detected in one (2%) vehicle control animal and in 66% of asbestos-treated animals. The highest frequencies (90% to 98% of animals) and earliest appearances (5 to 6 months) of mesothelioma occurred with the two relatively straight MWCNT A and B. Mesotheliomas (84% to 94% of animals) appeared only slightly later (6 to 10 months) in rats treated with MWCNT C. MWCNT D, the most curved nanotube, caused mesotheliomas (40% to 70% of animals) later (11 to 20 months) in the 2 year study.

### Humans

No data on the carcinogenicity of MWCNTs in humans were available. Because of the relatively recent production and use of MWCNT, worker exposures have been of relatively short duration. A few short-term studies have reported biomonitoring endpoints associated with exposure to MWCNTs; however, epidemiological studies designed to investigate the potential carcinogenicity of MWCNTs in humans have not been conducted. The carcinogenicity of CNTs was assessed by an IARC working group.^73^ MWCNT-7 was classified as possibly carcinogenic to humans (Group 2B). The lack of evidence across the various distinct CNTs precluded generalization to other types of CNTs. SWCNTs and MWCNTs, excluding MWCNT-7, were categorized as not classifiable as to their carcinogenicity to humans (Group 3).

## Genetic Toxicity

Carbon nanotubes have been reported to produce genotoxic effects in vivo and in vitro, yet few studies have attempted to systematically identify the key physicochemical characteristics that are required for inducing genotoxicity. For extensive reviews on the challenges of evaluating carbon nanotubes in genetic toxicity tests and recommendations for testing, as well as proposed mechanisms of action in vivo and in vitro, see Magdolenova et al.,^74^ IARC,^73^ Kuempel et al.,^75^ and Møller and Jacobsen.^76^ In general, the genotoxicity of carbon nanotubes has been attributed to formation of reactive oxygen species and interference with chromosome segregation. Carbon nanotubes have been tested in bacterial mutagenicity assays and have generally produced negative results; however, the use of these assays as part of a genetic toxicity testing battery for carbon nanotubes has been questioned, as nanotubes are unlikely to cross the cell wall.

Due to the heterogeneity of MWCNT, the following in vivo and in vitro genetic toxicology studies were reviewed depending on whether the tested material shared some characteristics with the National Toxicology Program (NTP) test article. Furthermore, in vivo studies were reviewed if inhalation was used as the route of exposure, similar to the NTP studies of L-MWNT-1020.

Three studies have evaluated the genotoxicity of MWCNT in rats exposed via inhalation. Two of these studies were performed by the same research group. In the first study, male Sprague Dawley rats underwent whole-body exposure to CM-95 MWCNT (Hanwha Nanotech, Inc. Incheon, Korea) for 5 days, 6 hours per day, at 0.16, 0.34, or 0.94 mg/m.^3,77^ CM-95 aerosols consisted of well-dispersed, straight fibers, ranging from 0.5 to 20 µm in length, with an average length of approximately 2.6 µm and diameters ranging from 10 to 15 nm. CM-95 consisted of approximately 95% carbon with approximately 5% metal impurities. Lung tissue was analyzed for DNA damage using the comet assay after the last exposure or after a recovery period of 1 month. At both timepoints, a significant increase in DNA damage was observed in the lung cells of rats exposed to 0.94 mg/m^3^. A significant increase in the concentration of hydrogen peroxide was observed in BALF in the 0.94 mg/m^3^ group after 1 month of recovery. Using dark field imaging, MWCNT were detected in lung tissue when assessed after the last exposure and after 1 month of recovery.

In the second study, male and female Fischer 344/N Slc rats underwent nose-only inhalation exposure to aerosolized CM-100 MWCNT (Hanwha Nanotech, Inc.) for 28 days, 6 hours per day, at 0.17, 0.49, or 0.96 mg/m.^3,78^ Although CM-95 and CM-100 had nearly identical product information (including length), CM-100 aerosols consisted of well-dispersed, straight fibers that ranged from 0.068 to 1.5 µm in length, with an average length of approximately 0.33 µm. The diameter was not reported. Lung tissue was analyzed for DNA damage using the comet assay after the last exposure or after a recovery period of 3 months. In both male and female rats, significant increases in DNA damage were observed at all concentrations of CM-100 after the last exposure. Small but significant increases in DNA damage were observed in both male and female rats after 3 months of recovery at the higher exposure concentrations. Significant changes in the concentration of hydrogen peroxide were detected in BALF samples from male, but not female, rats. Using dark field imaging, MWCNT were detected in lung tissue when assessed after the last exposure and after 3 months of recovery.

In a third study, male and female Wistar rats were exposed by nose-only inhalation for 5 days per week, 6 hours per day, over a period of 90 days to 0.05, 0.25, or 5 mg/m^3^ MWCNT (Graphistrength^©^ C100).^55^ The Graphistrength^©^ aerosols consisted of agglomerates of tangled MWCNTs with a MMAD of less than 3 µm. Micronuclei were assessed in bone marrow at 24 hours after the last exposure. There was no increase in micronucleated polychromatic erythrocytes (MN-PCEs) in male or female Wistar rats, and exposure to Graphistrength^©^ did not affect the percentage of MN-PCEs. Lung, kidney, and liver cells did not show increases in DNA damage (% tail DNA) when evaluated using a standard comet assay, or when evaluated in a modified comet assay using human 8-oxoguanidine DNA N-glycosylase 1 to detect DNA damage that can arise due to oxidative stress. In histological preparations, deposits of MWCNT aggregates were observed in lung tissue, but not in bone marrow, kidney, or liver tissue 24 hours after cessation of exposure. Taken together, these results suggest that MWCNTs are capable of inducing DNA damage in rats when inhaled; however, the genotoxic potential of MWCNTs appears to be dependent on their physicochemical characteristics.

Micronuclei and DNA damage were assessed in human lung carcinoma A549 cells using MWCNTs synthesized in the laboratory and purified to greater than 95% purity.^79^ The MWCNTs were approximately 10 to 20 µm in length, similar to L-MWNT-1020. The diameter was not reported. The MWCNTs tended to agglomerate in suspension and were sonicated prior to use. Small but significant increases in micronuclei were observed in A549 cells exposed to 12.5 µg/mL MWCNT for 3 hours, then incubated for 24 hours before harvest and analysis in a cytokinesis block micronucleus assay. Functionalized MWCNT, produced by carboxylation (–COOH) of the MWCNT, did not show an effect in the assay; however, the functionalization process also reduced the length of the MWCNT–COOH to about 0.2 to 1 µm. DNA damage was significantly increased in the comet assay in A549 cells exposed to MWCNT for 1 hour, and a modified version of the assay using formamidopyrimidine DNA glycosylase indicated the presence of oxidative damage to DNA. Similar to findings with the cytokinesis block micronucleus assay, MWCNT had a greater effect in the comet assay compared with MWCNT–COOH.

## Study Rationale

Nanoscale materials were nominated by the Rice University Center for Biological and Environmental Nanotechnology to NTP for toxicologic testing in 2003 because of intense current and anticipated future research and development focused on nanotechnology. An evaluation of high aspect ratio carbon materials, such as MWCNTs, was included as part of the original nomination. The NTP Nanotechnology Safety Initiative included MWCNTs as a major class of nanoscale materials for investigation. MWCNTs are available for purchase commercially, so there is potential for human exposure at some point in the product life cycle. MWCNTs were selected for study because of concern that they may pose a human health hazard on the basis of the reported induction of granulomas in rodents after pulmonary instillation of SWCNTs, and reported inflammatory responses to some MWCNTs after both intratracheal instillation and subchronic inhalation.^2,40,52-54,80,81^

Although some MWCNTs have been evaluated by subchronic inhalation exposure, the physical aspects and purity of commercially available MWCNTs are diverse. A variety of different carbon nanotubes are commercially available (including single-, double- or multiwalled) that range from less than 1 μm to more than 10 μm long and that have tube diameters that range from 1 nm to 100 nm. MWCNT are also available with or without surface functionalizations (–OH [hydroxylation] and –COOH) and can be in free form or arrayed on solid matrices. There is essentially no single representative type of MWCNT that is applicable to all MWCNTs, and it is not known which particular MWCNTs are anticipated to pose the highest exposure or hazard to humans. The primary objective of this study was to evaluate lung burden and clearance of a well-characterized long, thin MWCNT following inhalation exposure.

To aid with selecting a test article for study, 24 different MWCNTs were procured and characterized for identity, purity, metals content, physical appearance, and diameter size. These 24 MWCNTs exemplified the various tube lengths and diameters that are commercially available from various vendors. Following extensive chemical and physical evaluations of these 24 MWCNTs^82^ and inhalation feasibility studies of five of these MWCNTs, a 10–20 nm outer diameter and 10–30 µm long MWCNT (Sun Innovations, Inc; item number SN9847) was selected for study on the basis of availability, high purity, and the low amount of residual metal catalyst. This MWCNT represented a “thin” and “long” MWCNT for which few studies had been conducted. Because Chemical Abstracts Service numbers or standard nomenclature rules do not exist for CNT, the name “1020 Long Multiwalled Carbon Nanotubes/L-MWNT-1020” was assigned consistent with the manufacturer’s nominal characteristics of 10–30 μm length and 10–20 nm diameter. Unlike shorter, thicker, and more rigid MWCNTs, such longer, thinner, flexible MWCNTs form tangled agglomerates (“cotton balls”). This agglomerated morphology has been observed in human MWCNT-exposure environments. The chemical/physical characteristics of other CNTs with this designation or description may be different from those of the L-MWNT-1020 used in these studies.