# Appendix F Sentinel Animal Program

## F.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

In these studies on multiwalled carbon nanotubes, all samples were processed appropriately with serology performed by IDEXX Bioanalytics (formerly Research Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five animals per sex per timepoint.

Table F-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Multiplex Fluorescent Immunoassay
Kilham Rat Virus | 3 weeks and study termination
Mycoplasma pulmonis | 3 weeks and study termination
Parvo NS-1 | 3 weeks and study termination
Pneumonia Virus of Mice | 3 weeks and study termination
Rat Coronavirus/Sialodacryoadenitis Virus | 3 weeks and study termination
Rat Minute Virus | 3 weeks and study termination
Rat Parvovirus | 3 weeks and study termination
Rat Theilovirus (RTV) | 3 weeks and study termination
Sendai | 3 weeks and study termination
Theiler’s Murine Encephalomyelitis Virus | 3 weeks and study termination
Toolan’s H-1 | 3 weeks and study termination
Mice
Multiplex Fluorescent Immunoassay
Ectromelia Virus | 3 weeks and study termination
Epizootic Diarrhea of Infant Mice | 3 weeks and study termination
Lymphocytic Choriomeningitis Virus | 3 weeks and study termination
M. pulmonis | 3 weeks and study termination
Mouse Hepatitis Virus | 3 weeks and study termination
Mouse Norovirus | 3 weeks and study termination
Parvo NS-1 | 3 weeks and study termination
Minute Virus of Mice | 3 weeks and study termination
Mouse Parvovirus | 3 weeks and study termination
Pneumonia Virus of Mice | 3 weeks and study termination
Reovirus | 3 weeks and study termination
Sendai | 3 weeks and study termination
Theiler’s Murine Encephalomyelitis Virus | 3 weeks and study termination

## F.2 Results

All test results were negative.