# Appendix D Chemical Characterization and Generation of Chamber Concentrations

## D.1 Procurement and Characterization of 1020 Long Multiwalled Carbon Nanotubes

The test material—1020 Long Multiwalled Carbon Nanotube (L-MWNT-1020) nominal 10– 20 nm outer diameter, 1030 µm long multiwalled carbon nanotube (MWCNT)—was obtained from Sun Innovations, Inc. (Fremont, CA) in one lot (supplier item SN9847, supplier lot 10031301M) and was used in the 30-day studies. The study laboratory, Battelle Toxicology Northwest (Richland, WA), assigned the numbers 1 through 12 to the 12 amber glass containers received from the supplier. Identity and purity analyses were conducted by various analytical chemistry laboratories and by the study laboratory. Reports on analyses performed in support of the L-MWNT-1020 studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot 10031301M of the chemical, a dull black powder, was characterized by Environmental Molecular Sciences Laboratory (EMSL) at Pacific Northwest National Laboratory (PNNL) (Richland, WA) using transmission electron microscopy (TEM), scanning electron microscopy (SEM), Raman spectroscopy, energy dispersive X-ray spectroscopy (EDS), and X-ray photoelectron spectroscopy (XPS). In addition, lot 10031301M was characterized by Elemental Analysis, Inc. (Lexington, KY), using neutron activation analysis (NAA) and by Quantachrome Instruments (Boynton Beach, FL) using helium gas pycnometry (skeletal density), electrophoretic velocimetry (zeta potential), and Brunauer-Emmett-Teller (BET) gas adsorption analysis (surface area). All nine of these assessments were performed on bulk samples from the top, middle, and bottom of one container as received; in addition, single samples from the top of each of the other 11 containers received underwent Raman analysis.

TEM images confirmed test material identity by visualizing agglomerates of MWCNTs several micrometers in length and determined an average nanotube diameter of 15.3 nm (range: 6.1 to 26.7 nm). SEM estimated an average nanotube length of 2.6 µm (range: 0.6 to 7.4 µm). These averages (length of 2,600 nm and width of 15.3 nm) yielded an estimated length:width aspect ratio of 170:1 for the nanotubes in lot 10031301M.

Raman spectra of lot 10031301M contained spectral features consistent with those seen in spectra for commercially procured standards of similar graphitic materials, including G,G′, and D bands. A D′ band, typical of highly oxidized samples was not observed in the test material. Raman spectra of reference materials and L-MWNT-1020 are presented in Figure D-1.

EDS spectra indicated that nickel was present in the test material; subsequent NAA quantitated nickel at 0.52% by weight. None of the other elements quantitated by NAA (chlorine, cobalt, iron, and copper) were detected above 0.01%. XPS survey scans detected only carbon and oxygen on the surface of the test material. Subsequent high-resolution scans indicated the surface composition of the bulk chemical was approximately 98 atom % carbon and 2 atom % oxygen, consistent with literature values.^83,84^ BET gas adsorption analysis indicated an average surface area of 175 m^2^/g for lot 10031301M, consistent with values provided by the supplier. Skeletal density, as determined by helium gas pycnometry, was 2.0 g/cm^3^; this result was in good agreement with the density reported by the supplier. Measurement of the electrophoretic velocity of L-MWNT-1020 in distilled water yielded a zeta potential of −30 mV, consistent with published values for similar nanotube materials.^85^

The purity of lot 10031301M was determined by Galbraith Laboratories, Inc. (Knoxville, TN), using elemental analysis of samples from the top, middle, and bottom of one of the containers received and by Netzsch Instruments (Burlington, MA) using thermogravimetric analysis (TGA) of samples from the top, middle, and bottom of one container and one sample from each of the remaining containers received. The TGA method entailed combustion of samples of graphite, glassy carbon, and L-MWNT-1020 in a lidded crucible placed on a microbalance in a furnace. The samples were combusted in the presence of oxygen as the temperature was increased from 40°C to 950°C at 5°C/minute. The temporal profiles of mass changes, in conjunction with the residual mass and initial sample masses, were used to demonstrate that the TGA method was capable of discriminating between MWCNT and other forms of carbon and also to calculate the percent purity of the test material.

Elemental analysis for carbon, hydrogen, nitrogen, and sulfur indicated that lot 10031301M was 97% carbon by weight and the other elements assayed were below the quantitation limits of the method used (<0.5%). TGA estimated the average percent purity of L-MWNT-1020 as approximately 99% for all containers received. The overall purity of lot 10031301M was determined to be 97% or greater.

To ensure stability, the bulk test material was stored in the original 12 amber glass shipping jars at room temperature. Periodic reanalyses of the test material were performed by the study laboratory with TGA and Raman spectroscopy, and no degradation of the bulk test material was detected.

## D.2 Aerosol Generation and Exposure System

A schematic diagram of the L-MWNT-1020 aerosol generation and distribution system is shown in Figure D-2. The aerosol generation system consisted of a linear feed dust metering device to meter L-MWNT-1020 from a reservoir into an air stream. Within the metering device, periodic blasts of compressed air suspended small volumes of test material in the air stream for transport to the metering device exhaust tube. A particle attrition chamber was positioned immediately downstream of the metering device exhaust tube for initial particle size reduction of the test material. From the particle attrition chamber, the aerosol was passed through a single jet disperser into the distribution line. The single jet disperser assisted in further dispersion and particle size reduction. Downstream of the disperser jet, primary dilution air (filtered, compressed, humidified air) was added to increase the volumetric flow rate in the aerosol distribution line before the aerosol was passed through a cyclone separator. The cyclone separator removed the larger particles from the distribution system. The linear feed dust metering device, single jet disperser, the primary dilution air assembly and the cyclone separator were housed within a glove box located within the exposure control suite. Secondary dilution air (filtered, compressed, humidified air) was added outside of the glove box within the exposure control suite.

Within the distribution line, aerosol was conveyed from the exposure control suite to the exposure room. In the exposure room, the distribution line split into two lines for delivery to chambers situated on both sides of the exposure room. One branch (identified as the south distribution line in Figure D-2) transported aerosol to the 0.3, 1, and 3 mg/m^3^ chambers, and the second branch (identified as the north distribution line in Figure D-2) transported aerosol to the 0.1 and 10 mg/m^3^ chambers. During exposures, the air flow through the distribution lines was controlled using house vacuum regulated by a filter-protected flow meter. A second distribution line flow control system was available during off-exposure periods. This system consisted of a vacuum transducer pump (Air-Vac Engineering Co., Inc., Seymour, CT) of higher flow capacity positioned in parallel with the flow meter control assembly that became operational only during critical shut-down periods. High-efficiency particulate air (HEPA) filters were placed before the vacuum supply and transducer pump at the end of each delivery line to remove aerosol from the airstream prior to exhausting from the room. At each exposure chamber location, aerosol was directed from the distribution line by a sampling tube into the chamber conditioned air supply for mixing prior to delivery to the chamber. The flow through the sampling tube was induced by a stainless steel ejector pump designed and fabricated at Battelle. The flow rate and configuration of each ejector pump and sampling tube combination were chosen to optimize the efficiency of the delivery system and achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Lab Products, Inc., Seaford, DE) so that uniform aerosol concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. At each exposure concentration, the chambers housed both rats and mice from the concurrent studies.

## D.3 Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table D-1. The concentrations of L-MWNT-1020 in the exposure chambers and room air were monitored using three real-time aerosol monitors (RAMs; RAM-1, MIE, Inc., Bedford, MA, or MicroDust pro, Casella CEL, Ltd., Kempson, Bedford, England). The monitors were connected to the chambers through sample lines and a multiplexing valve designed to minimize aerosol losses caused by settling or impaction. Each RAM was multiplexed to the exposure chambers and/or the 0 mg/m^3^ chamber or the exposure room and a HEPA-filtered air blank. The output voltage of each RAM was recorded by the Battelle Exposure Data Acquisition and Control (BEDAC) software system and converted to mg/m^3^ exposure concentration by the application of a calibration curve. Each measured concentration was compared to limit values for the locations monitored by each RAM and, if a measured concentration exceeded its control limits, the BEDAC system triggered an audible alert or, in extreme cases, terminated the exposure.

Each RAM was calibrated by constructing a response curve using the measured RAM voltages (corrected for zero offset voltage measured in a HEPA-filtered airstream) and L-MWNT-1020 concentrations determined by gravimetric analysis of filter samples obtained from the exposure chambers. Duplicate exposure chamber atmosphere samples were collected each day on 25 mm Pallflex^®^ Emfab™ TX40H120WW Teflon^®^-coated, glass fiber filters (Pall Corporation, East Hills, NY). Validation studies demonstrated that gravimetric and chemical-specific measurements of chamber concentrations were comparable. An ultraviolet visible spectrophotometric assay was used for chemical-specific analysis of L-MWNT-1020. This assay used an off-line Agilent 1100/1200 liquid chromatograph (Agilent, Santa Clara, CA) to measure changes in absorbance (at 538 nm) of an aqueous solution that contained a dye (Procion^®^ Red MX-5B; Sigma-Aldrich, St. Louis, MO) that had an affinity for filter-trapped L-MWNT-1020.

The off-line chromatograph was calibrated using gravimetrically prepared calibration standards of the test article. These methods were demonstrated by the study laboratory to have adequate precision, accuracy, linear working range, day-to-day respectability, and detection limits for the L-MWNT-1020 concentrations in the exposure chambers.

## D.4 Chamber Atmosphere Characterization

Aerosol particle size distribution was determined once prior to and once during the 30-day studies by collecting aerosol samples from each exposure chamber using a Mercer-style cascade impactor. L-MWNT-1020 was collected (for stages one through seven) on 37 mm stainless steel slides lightly coated with silicone (Mercer Impactor 37 mm collection discs, In-Tox Products, LLC, Moriarty, NM) or (for stage eight) 47 mm Teflon-coated glass fiber filters (Pallflex^®^ Emfab™ TX40H120WW, Pall Corporation) to establish the mass median aerodynamic diameter (MMAD) of the aerosol particles. The impactor samples were analyzed gravimetrically to determine the amount of L-MWNT-1020 collected on each stage. The relative mass of L-MWNT-1020 collected on each impactor stage was analyzed by the NEWCAS impactor analysis program developed at the study laboratory based on probit analysis.^86^ The resulting particle size distributions for chamber atmosphere samples collected during the studies are summarized in Table D-2; MMAD values were below the 3.0 µm upper limit criterion required by the design of the studies.

For each exposure chamber, the count median diameter (CMD) for the aerosol and the number of particles per unit volume were determined once before and once during the 30-day studies using an electrical low pressure impactor (ELPI; Dekati Ltd., Kongsala, Finland). The ELPI counted the number of particles in 12 size bins within a size range of 0.03 to 10 µm. The CMD and particle number concentration were analyzed using the ELPI VI 4.0 Data Analysis Software provided by the manufacturer. The results for chamber atmosphere sample collected during the studies are summarized in Table D-3; CMDs for the aerosol ranged from 92 to 99 nm with the number of particles varying from 3.5 × 10^4^ to 1.1 × 10^6^ particles/cm^3^.

Buildup and decay rates for chamber aerosol concentrations were determined at two ports for each chamber with and without animals present in the chambers. At a chamber airflow rate of 15 ft^3^/minute, the theoretical value for the time to achieve 90% of the target concentration after the beginning of aerosol generation (T_90_) was approximately 9.2 minutes and the time for the chamber concentration to decay to 10% of the target concentration after aerosol generation was terminated (T_10_) was approximately 12 minutes. For rats and mice in the 30-day studies, T_90_ values ranged from 7 to 12 minutes without animals present and from 8 to 15 minutes with animals; T_10_ values ranged from 8 to 11 minutes without animals present and from 5 to 16 minutes with animals. A T_90_ value of 12 minutes was selected for the studies.

The uniformity of aerosol concentration in the inhalation exposure chambers without animals was evaluated before the studies began; in addition, concentration uniformity with animals present in the chamber was measured once during the 30-day studies. Aerosol concentrations were measured using the on-line monitor system with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. Concentrations were measured at all 12 sample ports; one in front and one in back for each of six possible animal cage unit positions per chamber. Chamber concentration uniformity was maintained throughout the studies.

The persistence of L-MWNT-1020 in the chambers after aerosol delivery ended was determined by monitoring the concentration overnight in the 10 mg/m^3^ chamber in the 30-day studies with and without animals present in the chamber. The concentration decreased to 1% of the target concentration within 14 minutes with animals present and within 18 minutes without animals.

Stability studies of L-MWNT-1020 in the generation and delivery system were performed before and during the studies by EMSL/PNNL (TEM, Raman spectroscopy, and XPS), Quantachrome Instruments (BET surface area), Netzsch Instruments (TGA), and the study laboratory (elemental analysis by inductively coupled plasma/atomic emission spectroscopy [ICP/AES]). On each sample collection day, a sample of the bulk test material used to fill the generator reservoir was taken prior to filling the reservoir, and a sample of the test material from the generator reservoir was collected at the end of the generation day (additional bulk chemical was added to the generator each day). All six stability characterization assessments (TEM, BET, Raman spectroscopy, XPS, TGA, and elemental analysis) were performed on these bulk chemical and generator reservoir samples. All of these assessments were also performed on aerosol samples obtained from the distribution line and the 0.1 (except for BET analysis) and 10 mg/m^3^ exposure chambers. Aerosolized samples for TEM imagery were collected using an electrostatic precipitation and by impaction onto TEM grids mounted on glass fiber filters. Aerosolized samples for BET surface area analysis were collected onto 47 mm glass fiber filters (Performance Systematix, Inc., Grand Rapids, MI), those for Raman spectral analysis and XPS were collected onto 25 mm silver membrane filters (Sterlitech Corp., Kent, WA), and those for TGA and elemental analysis were collected onto 25 mm glass fiber (Pallflex Tissuquartz) or GH Polypro filters (Pall Corporation). BET analysis included assessments of a reference standard and TGA analysis included additional filter sample taken from the 0 mg/m^3^ chamber.

TEM imagery indicated that the morphology of the test material collected from the exposure aerosol was qualitatively similar to that observed in the bulk material. BET surface area analysis determined that the surface area of the test material in the exposure system was generally comparable to the results of the initial characterization tests of lot 10031301M. Raman spectra of L-MWNT-1020 collected from the exposure system were consistent with Raman spectra of the bulk chemical as determined in the initial test chemical characterization. XPS surface scans of the exposure system aerosol samples indicated that the surface of L-MWNT-1020 included carbon and oxygen. Overall, the oxygen surface atom percentage was less than 5%, indicating that substantial oxidation of the test chemical did not occur during generation of aerosolized exposure atmospheres. No impurities or degradation products were detected by TGA in any of the exposure atmosphere aerosol samples; analyses conducted on samples collected before and after the 30-day studies indicated a purity greater than or equal to 98%, consistent with the approximate 99% purity estimate derived by TGA analysis of the bulk chemical during the initial purity measurements of lot 10031301M. ICP/AES determination of the levels of 18 elements in microwave-assisted digests of the samples collected from the exposure system indicated all elements measured in the samples were less than their low standards except nickel, sulfur, and iron (during the 30-day studies only). These results were consistent with elemental analyses of the bulk test material in the initial characterization of the test chemical.

Taken together, these results demonstrated that the exposure atmosphere and generator reservoir samples were in good agreement with the bulk test article, the composition of L-MWNT-1020 was stable in the exposure system, and contamination from metal materials in the exposure system did not occur.

Table D-1 Summary of Chamber Concentrations in the 30-day Inhalation Studies of 1020 Long Multiwalled Carbon Nanotubes

| Total Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Rat Chambers
| 0.1 | 179 | 0.10 ± 0.01
| 0.3 | 179 | 0.30 ± 0.01
| 1 | 192 | 0.98 ± 0.05
| 3 | 180 | 2.96 ± 0.18
| 10 | 179 | 10.01 ± 0.40
Mouse Chambers
| 0.1 | 177 | 0.10 ± 0.01
| 0.3 | 177 | 0.30 ± 0.02
| 1 | 186 | 0.99 ± 0.05
| 3 | 180 | 2.95 ± 0.17
| 10 | 177 | 9.97 ± 0.42

^a^ Mean ± standard deviation.

Table D-2 Summary of Aerosol Size Measurements for Rat and Mouse Exposure Chambers in the 30-day Inhalation Studies of 1020 Long Multiwalled Carbon Nanotubes

Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
0.1 | 1.7 | 2.6
0.3 | 2.3 | 2.5
1 | 2.8 | 2.1
3 | 2.0 | 2.6
10 | 2.2 | 2.2

Table D-3 Summary of Aerosol Count Median Diameters and Particle Number Concentrations for Rat and Mouse Exposure Chambers in the 30-day Inhalation Studies of 1020 Long Multiwalled Carbon Nanotubes

Target Concentration (mg/m^3^) | Count Median Diameter (µm) | Number of Particles/cm^3^
0.1 | 96 | 3.5 × 10^4^
0.3 | 95 | 7.8 × 10^4^
1 | 92 | 2.5 × 10^5^
3 | 94 | 4.9 × 10^5^
10 | 99 | 1.1 × 10^6^

Figure D-1

Raman Spectra of Graphitic Materials in the 30-day Inhalation Studies of 1020 Long Multiwalled Carbon Nanotubes

A) Graphite, B) glassy carbon, C) commercially procured MWCNT standard, D) test material (lot 10031301M).

Figure D-2

Schematic of the Aerosol Generation and Delivery System in the 30-day Inhalation Studies of 1020 Long Multiwalled Carbon Nanotubes