# Appendix C Lung Burden Results

Table C-1 Postexposure Survival and Body Weights of Lung Burden Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
Day 0
0 | 10/10 | 121 ± 3 | 268 ± 6 | 147 ± 5
0.1 | 10/10 | 124 ± 3 | 275 ± 4 | 151 ± 4 | 103
0.3 | 10/10 | 124 ± 3 | 259 ± 5 | 136 ± 4 | 97
1 | 10/10 | 122 ± 2 | 262 ± 9 | 141 ± 8 | 98
3 | 10/10 | 122 ± 4 | 276 ± 8 | 154 ± 6 | 103
10 | 10/10 | 114 ± 2 | 261 ± 6 | 147 ± 5 | 97
Day 14
0 | 5/5 | 122 ± 5 | 295 ± 18 | 172 ± 16
0.1 | 5/5 | 117 ± 4 | 304 ± 14 | 188 ± 11 | 103
0.3 | 5/5 | 118 ± 5 | 305 ± 8 | 187 ± 9 | 103
1 | 5/5 | 119 ± 4 | 304 ± 5 | 185 ± 2 | 103
3 | 5/5 | 121 ± 6 | 323 ± 7 | 202 ± 3 | 110
10 | 5/5 | 124 ± 5 | 320 ± 12 | 196 ± 10 | 108
Day 42
0 | 5/5 | 117 ± 5 | 361 ± 9 | 244 ± 9
0.1 | 5/5 | 122 ± 4 | 364 ± 16 | 242 ± 12 | 101
0.3 | 5/5 | 123 ± 5 | 357 ± 13 | 234 ± 13 | 99
1 | 5/5 | 128 ± 6 | 376 ± 15 | 249 ± 11 | 104
3 | 5/5 | 116 ± 4 | 379 ± 10 | 263 ± 7 | 105
10 | 5/5 | 126 ± 5 | 363 ± 18 | 237 ± 16 | 100
Day 126
0 | 5/5 | 124 ± 4 | 437 ± 36 | 313 ± 33
0.1 | 5/5 | 123 ± 3 | 429 ± 7 | 307 ± 6 | 98
0.3 | 5/5 | 121 ± 3 | 431 ± 5 | 310 ± 5 | 99
1 | 5/5 | 121 ± 3 | 445 ± 10 | 325 ± 11 | 102
3 | 5/5 | 115 ± 4 | 425 ± 16 | 310 ± 14 | 97
10 | 5/5 | 121 ± 4 | 451 ± 12 | 330 ± 14 | 103
Female
Day 0
0 | 10/10 | 109 ± 2 | 182 ± 3 | 72 ± 3
0.1 | 10/10 | 108 ± 2 | 182 ± 3 | 74 ± 2 | 100
0.3 | 10/10 | 103 ± 1 | 180 ± 3 | 77 ± 3 | 99
1 | 10/10 | 106 ± 2 | 177 ± 3 | 71 ± 2 | 97
3 | 10/10 | 109 ± 2 | 186 ± 2 | 77 ± 2 | 102
10 | 10/10 | 108 ± 2 | 186 ± 4 | 77 ± 3 | 102
Day 14
0 | 5/5 | 107 ± 3 | 207 ± 4 | 100 ± 4
0.1 | 5/5 | 108 ± 3 | 204 ± 10 | 95 ± 8 | 98
0.3 | 5/5 | 103 ± 3 | 193 ± 3 | 90 ± 2 | 94
1 | 5/5 | 105 ± 2 | 205 ± 5 | 101 ± 5 | 99
3 | 5/5 | 105 ± 3 | 202 ± 5 | 97 ± 3 | 98
10 | 5/5 | 105 ± 2 | 207 ± 6 | 101 ± 5 | 100
Day 42
0 | 5/5 | 108 ± 4 | 223 ± 5 | 115 ± 4
0.1 | 5/5 | 107 ± 3 | 229 ± 7 | 122 ± 7 | 103
0.3 | 5/5 | 104 ± 5 | 225 ± 5 | 122 ± 5 | 101
1 | 5/5 | 108 ± 2 | 235 ± 4 | 127 ± 3 | 105
3 | 5/5 | 102 ± 2 | 229 ± 5 | 127 ± 6 | 103
10 | 5/5 | 104 ± 1 | 215 ± 3 | 111 ± 3 | 97
Day 126
0 | 5/5 | 108 ± 3 | 256 ± 3 | 147 ± 3
0.1 | 5/5 | 108 ± 3 | 264 ± 5 | 156 ± 7 | 103
0.3 | 5/5 | 112 ± 2 | 263 ± 8 | 152 ± 7 | 103
1 | 5/5 | 105 ± 5 | 260 ± 9 | 155 ± 7 | 102
3 | 5/5 | 105 ± 3 | 268 ± 7 | 163 ± 4 | 105
10 | 5/5 | 108 ± 2 | 264 ± 4 | 155 ± 4 | 103

^a^ Weights and weight changes are given as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at the scheduled euthanasia/number initially in group.

Table C-2 Postexposure Survival and Body Weights of Lung Burden Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
Day 0
0 | 10/10 | 22.5 ± 0.5 | 25.8 ± 0.5 | 3.3 ± 0.2
0.1 | 10/10 | 22.2 ± 0.3 | 25.3 ± 0.3 | 3.1 ± 0.2 | 98
0.3 | 10/10 | 22.0 ± 0.2 | 24.9 ± 0.3 | 2.9 ± 0.3 | 97
1 | 10/10 | 21.6 ± 0.2 | 24.9 ± 0.3 | 3.3 ± 0.2 | 97
3 | 10/10 | 22.3 ± 0.2 | 25.4 ± 0.4 | 3.1 ± 0.3 | 98
10 | 10/10 | 22.8 ± 0.4 | 26.0 ± 0.5 | 3.2 ± 0.3 | 101
Day 14
0 | 5/5 | 22.2 ± 0.2 | 27.4 ± 0.4 | 5.2 ± 0.2
0.1 | 5/5 | 22.6 ± 0.6 | 27.4 ± 0.7 | 4.8 ± 0.4 | 100
0.3 | 5/5 | 22.3 ± 0.6 | 27.4 ± 0.4 | 5.1 ± 0.5 | 100
1 | 5/5 | 22.8 ± 0.4 | 27.3 ± 0.5 | 4.5 ± 0.5 | 100
3 | 5/5 | 21.5 ± 0.4 | 27.2 ± 0.5 | 5.6 ± 0.3 | 99
10 | 5/5 | 21.3 ± 0.5 | 25.6 ± 0.7 | 4.3 ± 0.5 | 94
Day 42
0 | 5/5 | 22.0 ± 0.2 | 30.3 ± 0.3 | 8.4 ± 0.2
0.1 | 5/5 | 21.2 ± 0.4 | 30.0 ± 0.7 | 8.8 ± 0.6 | 99
0.3 | 5/5 | 22.1 ± 0.3 | 29.7 ± 1.0 | 7.5 ± 0.8 | 98
1 | 5/5 | 21.9 ± 0.6 | 29.9 ± 0.8 | 8.0 ± 0.9 | 99
3 | 5/5 | 22.5 ± 0.6 | 32.2 ± 1.5 | 9.6 ± 1.0 | 106
10 | 5/5 | 22.5 ± 0.4 | 31.3 ± 0.6 | 8.8 ± 0.7 | 103
Day 126
0 | 5/5 | 22.5 ± 0.6 | 41.0 ± 1.5 | 18.5 ± 1.3
0.1 | 5/5 | 21.8 ± 0.6 | 40.2 ± 2.6 | 18.4 ± 2.0 | 98
0.3 | 5/5 | 22.9 ± 0.3 | 39.0 ± 0.8 | 16.2 ± 0.6 | 95
1 | 5/5 | 23.2 ± 0.3 | 41.0 ± 0.8 | 17.8 ± 1.0 | 100
3 | 5/5 | 22.2 ± 0.6 | 39.8 ± 1.7 | 17.7 ± 1.3 | 97
10 | 5/5 | 22.0 ± 0.3 | 42.0 ± 0.8 | 20.1 ± 0.6 | 102
Female
Day 0
0 | 10/10 | 18.9 ± 0.2 | 21.6 ± 0.2 | 2.7 ± 0.1
0.1 | 10/10 | 19.7 ± 0.4 | 22.3 ± 0.3 | 2.7 ± 0.3 | 103
0.3 | 10/10 | 19.0 ± 0.3 | 21.6 ± 0.4 | 2.6 ± 0.3 | 100
1 | 10/10 | 19.1 ± 0.2 | 22.0 ± 0.3 | 2.9 ± 0.2 | 102
3 | 10/10 | 19.1 ± 0.3 | 21.4 ± 0.3 | 2.3 ± 0.2 | 99
10 | 10/10 | 18.5 ± 0.3 | 21.0 ± 0.2 | 2.4 ± 0.2 | 97
Day 14
0 | 5/5 | 18.9 ± 0.6 | 23.9 ± 0.5 | 5.0 ± 0.5
0.1 | 5/5 | 18.3 ± 0.4 | 22.8 ± 0.6 | 4.5 ± 0.3 | 96
0.3 | 5/5 | 19.1 ± 0.5 | 23.0 ± 0.7 | 3.9 ± 0.2 | 96
1 | 5/5 | 19.4 ± 0.3 | 24.3 ± 0.2 | 4.9 ± 0.3 | 102
3 | 5/5 | 18.1 ± 0.7 | 22.6 ± 0.2 | 4.5 ± 0.5 | 95
10 | 5/5 | 19.5 ± 0.4 | 24.0 ± 0.8 | 4.5 ± 0.4 | 100
Day 42
0 | 5/5 | 18.9 ± 0.5 | 25.9 ± 0.7 | 7.0 ± 0.5
0.1 | 5/5 | 18.8 ± 0.5 | 24.1 ± 0.7 | 5.3 ± 0.5 | 93
0.3 | 5/5 | 19.3 ± 0.7 | 24.8 ± 0.3 | 5.5 ± 0.5 | 96
1 | 5/5 | 19.0 ± 0.3 | 25.7 ± 0.6 | 6.7 ± 0.5 | 99
3 | 5/5 | 19.0 ± 0.2 | 24.8 ± 0.5 | 5.9 ± 0.5 | 96
10 | 5/5 | 18.6 ± 0.4 | 25.8 ± 0.7 | 7.2 ± 0.6 | 100
Day 126
0 | 5/5 | 20.1 ± 0.4 | 37.3 ± 0.9 | 17.2 ± 0.9
0.1 | 5/5 | 18.8 ± 0.2 | 37.5 ± 1.3 | 18.7 ± 1.2 | 101
0.3 | 5/5 | 19.3 ± 0.6 | 38.1 ± 1.3 | 18.8 ± 0.9 | 102
1 | 5/5 | 18.0 ± 0.2** | 33.6 ± 2.3 | 15.6 ± 2.3 | 90
3 | 5/5 | 19.3 ± 0.3 | 37.4 ± 2.1 | 18.1 ± 1.9 | 100
10 | 5/5 | 18.8 ± 0.5 | 30.8 ± 1.0* | 12.0 ± 1.3 | 83

* Significantly different (p ≤ 0.05) from the chamber control group by Dunnett’s test.

** p ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at the scheduled euthanasia/number initially in group.

Figure C-1

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 0.1 mg/m^3^ Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

Figure C-2

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 0.3 mg/m^3^ Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

Figure C-3

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 1 mg/m^3^ Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

Figure C-4

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 3 mg/m^3^ Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

Figure C-5

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 10 mg/m^3^ Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

Figure C-6

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 0.1 mg/m^3^ Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

Figure C-7

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 0.3 mg/m^3^ Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

Figure C-8

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 1 mg/m^3^ Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

Figure C-9

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 3 mg/m^3^ Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes

Figure C-10

Lung 1020 Long Multiwalled Carbon Nanotube Burdens in 10 mg/m^3^ Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes