# Appendix B Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table B-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy Body Wt. | 288 ± 6 | 291 ± 4 | 280 ± 5 | 282 ± 7 | 291 ± 4 | 289 ± 7
Heart
Absolute | 1.106 ± 0.035 | 1.122 ± 0.018 | 1.051 ± 0.020 | 1.085 ± 0.031 | 1.119 ± 0.023 | 1.100 ± 0.040
Relative | 3.83 ± 0.08 | 3.85 ± 0.05 | 3.75 ± 0.06 | 3.85 ± 0.05 | 3.84 ± 0.05 | 3.80 ± 0.09
R. Kidney
Absolute | 1.112 ± 0.030 | 1.155 ± 0.026 | 1.070 ± 0.017 | 1.077 ± 0.036 | 1.107 ± 0.015 | 1.108 ± 0.037
Relative | 3.86 ± 0.08 | 3.96 ± 0.06 | 3.82 ± 0.08 | 3.82 ± 0.04 | 3.81 ± 0.04 | 3.83 ± 0.08
Liver
Absolute | 12.59 ± 0.536 | 12.09 ± 0.397 | 11.13 ± 0.330 | 11.58 ± 0.436 | 12.52 ± 0.515 | 12.11 ± 0.551
Relative | 43.62 ± 1.56 | 41.48 ± 1.24 | 39.63 ± 0.73 | 41.04 ± 0.92 | 42.97 ± 1.53 | 41.82 ± 1.43
Lung
Absolute | 2.143 ± 0.128 | 2.055 ± 0.122 | 1.777 ± 0.063* | 1.950 ± 0.076 | 2.047 ± 0.078 | 2.143 ± 0.078
Relative | 7.43 ± 0.42 | 7.05 ± 0.39 | 6.34 ± 0.22 | 6.94 ± 0.28 | 7.04 ± 0.26 | 7.43 ± 0.24
R. Testis
Absolute | 1.842 ± 0.037 | 1.819 ± 0.022 | 1.745 ± 0.053 | 1.845 ± 0.034 | 1.743 ± 0.038 | 1.732 ± 0.038
Relative | 6.41 ± 0.17 | 6.25 ± 0.07 | 6.23 ± 0.17 | 6.56 ± 0.10 | 6.00 ± 0.14 | 6.02 ± 0.15
Thymus
Absolute | 0.640 ± 0.020 | 0.627 ± 0.043 | 0.603 ± 0.034 | 0.589 ± 0.022 | 0.651 ± 0.019 | 0.643 ± 0.033
Relative | 2.22 ± 0.07 | 2.16 ± 0.17 | 2.15 ± 0.11 | 2.09 ± 0.05 | 2.24 ± 0.08 | 2.22 ± 0.09
Female
Necropsy Body Wt. | 194 ± 3 | 192 ± 5 | 195 ± 3 | 191 ± 3 | 195 ± 4 | 194 ± 4
Heart
Absolute | 0.777 ± 0.019 | 0.788 ± 0.029 | 0.797 ± 0.018 | 0.785 ± 0.020 | 0.772 ± 0.025 | 0.797 ± 0.026
Relative | 4.00 ± 0.07 | 4.11 ± 0.09 | 4.08 ± 0.06 | 4.10 ± 0.07 | 3.95 ± 0.08 | 4.11 ± 0.08
R. Kidney
Absolute | 0.748 ± 0.013 | 0.778 ± 0.019 | 0.772 ± 0.017 | 0.783 ± 0.016 | 0.754 ± 0.017 | 0.751 ± 0.023
Relative | 3.86 ± 0.06 | 4.07 ± 0.08 | 3.95 ± 0.06 | 4.09 ± 0.06* | 3.86 ± 0.07 | 3.87 ± 0.06
Liver
Absolute | 7.717 ± 0.225 | 7.274 ± 0.286 | 7.216 ± 0.246 | 7.304 ± 0.208 | 7.393 ± 0.288 | 7.337 ± 0.236
Relative | 39.74 ± 0.80 | 37.90 ± 0.84 | 36.90 ± 0.82 | 38.11 ± 0.68 | 37.76 ± 0.87 | 37.85 ± 0.73
Lung
Absolute | 1.417 ± 0.046 | 1.319 ± 0.031 | 1.408 ± 0.047 | 1.482 ± 0.042 | 1.498 ± 0.046 | 1.765 ± 0.046**
Relative | 7.31 ± 0.24 | 6.90 ± 0.11 | 7.22 ± 0.22 | 7.74 ± 0.19 | 7.66 ± 0.10 | 9.14 ± 0.27**
Thymus
Absolute | 0.444 ± 0.009 | 0.464 ± 0.026 | 0.440 ± 0.015 | 0.442 ± 0.021 | 0.493 ± 0.016 | 0.455 ± 0.018
Relative | 2.29 ± 0.05 | 2.41 ± 0.09 | 2.26 ± 0.07 | 2.31 ± 0.11 | 2.52 ± 0.06 | 2.36 ± 0.10

* Significantly different (p ≤ 0.05) from the chamber control group by Dunnett’s test.

** Significantly different (p ≤ 0.01) from the chamber control group by Williams’ test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table B-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy Body Wt. | 27.9 ± 0.4 | 27.6 ± 0.3 | 27.3 ± 0.5 | 27.2 ± 0.3 | 27.5 ± 0.5 | 27.8 ± 0.5
Heart
Absolute | 0.130 ± 0.001 | 0.130 ± 0.003 | 0.130 ± 0.003 | 0.126 ± 0.002 | 0.130 ± 0.004 | 0.135 ± 0.004
Relative | 4.67 ± 0.08 | 4.71 ± 0.07 | 4.76 ± 0.07 | 4.65 ± 0.08 | 4.73 ± 0.11 | 4.85 ± 0.07
R. Kidney
Absolute | 0.243 ± 0.006 | 0.257 ± 0.007 | 0.247 ± 0.006 | 0.244 ± 0.005 | 0.253 ± 0.006 | 0.254 ± 0.007
Relative | 8.73 ± 0.18 | 9.31 ± 0.18 | 9.05 ± 0.19 | 9.00 ± 0.18 | 9.21 ± 0.12 | 9.12 ± 0.16
Liver
Absolute | 1.292 ± 0.046 | 1.310 ± 0.041 | 1.309 ± 0.029 | 1.295 ± 0.022 | 1.347 ± 0.038 | 1.290 ± 0.041
Relative | 46.32 ± 1.33 | 47.41 ± 1.00 | 47.97 ± 0.95 | 47.73 ± 0.78 | 49.05 ± 0.92 | 46.31 ± 1.02
Lung
Absolute | 0.184 ± 0.006 | 0.188 ± 0.006 | 0.184 ± 0.004 | 0.192 ± 0.004 | 0.210 ± 0.002** | 0.258 ± 0.004**
Relative | 6.61 ± 0.21 | 6.82 ± 0.19 | 6.73 ± 0.08 | 7.08 ± 0.16 | 7.67 ± 0.13** | 9.29 ± 0.19**
R. Testis
Absolute | 0.101 ± 0.003 | 0.104 ± 0.002 | 0.100 ± 0.003 | 0.102 ± 0.002 | 0.098 ± 0.003 | 0.099 ± 0.004
Relative | 3.63 ± 0.08 | 3.79 ± 0.10 | 3.65 ± 0.09 | 3.75 ± 0.05 | 3.58 ± 0.10 | 3.55 ± 0.16
Thymus
Absolute | 0.061 ± 0.003 | 0.061 ± 0.003 | 0.065 ± 0.002 | 0.065 ± 0.002 | 0.062 ± 0.003 | 0.066 ± 0.003
Relative | 2.17 ± 0.10 | 2.22 ± 0.08 | 2.37 ± 0.10 | 2.41 ± 0.08 | 2.27 ± 0.09 | 2.36 ± 0.10
Female
Necropsy Body Wt. | 24.4 ± 0.5 | 24.1 ± 0.4 | 24.5 ± 0.4 | 24.7 ± 0.3 | 23.8 ± 0.3 | 24.8 ± 0.3
Heart
Absolute | 0.122 ± 0.002 | 0.118 ± 0.002 | 0.123 ± 0.002 | 0.123 ± 0.002 | 0.120 ± 0.002 | 0.122 ± 0.001
Relative | 5.00 ± 0.12 | 4.91 ± 0.09 | 5.03 ± 0.08 | 4.98 ± 0.10 | 5.05 ± 0.10 | 4.93 ± 0.09
R. Kidney
Absolute | 0.179 ± 0.006 | 0.182 ± 0.004 | 0.185 ± 0.005 | 0.189 ± 0.003 | 0.185 ± 0.004 | 0.190 ± 0.005
Relative | 7.31 ± 0.17 | 7.56 ± 0.09 | 7.56 ± 0.13 | 7.65 ± 0.13 | 7.77 ± 0.13 | 7.66 ± 0.13
Liver
Absolute | 1.190 ± 0.035 | 1.162 ± 0.041 | 1.194 ± 0.040 | 1.191 ± 0.025 | 1.167 ± 0.025 | 1.187 ± 0.026
Relative | 48.68 ± 0.96 | 48.22 ± 1.28 | 48.74 ± 1.02 | 48.20 ± 0.91 | 49.03 ± 0.87 | 47.87 ± 0.84
Lung
Absolute | 0.180 ± 0.005 | 0.180 ± 0.004 | 0.188 ± 0.006 | 0.194 ± 0.007 | 0.199 ± 0.003* | 0.255 ± 0.005**
Relative | 7.37 ± 0.12 | 7.48 ± 0.12 | 7.68 ± 0.19 | 7.86 ± 0.30 | 8.36 ± 0.10** | 10.29 ± 0.17**
Thymus
Absolute | 0.074 ± 0.003 | 0.075 ± 0.002 | 0.075 ± 0.002 | 0.073 ± 0.002 | 0.071 ± 0.002 | 0.072 ± 0.002
Relative | 3.01 ± 0.08 | 3.14 ± 0.07 | 3.06 ± 0.06 | 2.96 ± 0.09 | 2.98 ± 0.06 | 2.91 ± 0.09

* Significantly different (p ≤ 0.05) from the chamber control group by Williams’ test.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).