# Appendix A Summary of Nonneoplastic Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
Disposition Summary
Animals Initially in Study | 35 | 35 | 35 | 35 | 35 | 35
Survivors
Terminal Euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Lung Burden Study | 25 | 25 | 25 | 25 | 25 | 25
Animals Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (0) | (1) | (0) | (0) | (0) | (0)
Necrosis, Focal | – | 1 (100%) | – | – | – | –
Pharynx | (10) | (10) | (10) | (10) | (10) | (10)
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
Lymph Node, Bronchial | (6) | (6) | (9) | (7) | (7) | (7)
Foreign Body | – | – | – | 4 (57%) | 6 (86%) | 7 (100%)
Hyperplasia, Lymphoid | – | – | – | – | 6 (86%) | 2 (29%)
Lymph Node, Mediastinal | (7) | (9) | (10) | (9) | (9) | (10)
Foreign Body | – | – | – | 3 (33%) | 8 (89%) | 10 (100%)
Hyperplasia, Lymphoid | – | 3 (33%) | 1 (10%) | 3 (33%) | 8 (89%) | 9 (90%)
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Larynx | (10) | (10) | (10) | (10) | (10) | (10)
Epiglottis, Metaplasia, Squamous | – | – | – | 1 (10%) | 9 (90%) | 9 (90%)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Foreign Body | | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Inflammation, Chronic | 5 (50%) | 1 (10%) | 2 (20%) | 10 (100%) | 10 (100%) | 10 (100%)
Alveolar Epithelium, Hyperplasia | – | – | – | 3 (30%) | 10 (100%) | 10 (100%)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Accumulation, Hyaline Droplet | – | 1 (10%) | 3 (30%) | – | – | 3 (30%)
Respiratory Epithelium, Accumulation, Hyaline Droplet | – | – | – | – | 1 (10%) | 1 (10%)
Trachea | (9) | (10) | (10) | (10) | (10) | (10)
Special Senses System
None | – | – | – | – | – | –
Urinary System
None | – | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
Disposition Summary
Animals Initially in Study | 35 | 35 | 35 | 35 | 35 | 35
Survivors
Terminal Euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Lung Burden Study | 25 | 25 | 25 | 25 | 25 | 25
Animals Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Pharynx | (10) | (10) | (10) | (10) | (10) | (10)
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Uterus | (0) | (0) | (0) | (1) | (0) | (0)
Endometrium, Hyperplasia, Cystic | – | – | – | 1 (100%) | – | –
Hematopoietic System
Lymph Node | (0) | (0) | (0) | (0) | (0) | (1)
Iliac, Pigmentation | – | – | – | – | – | 1 (100%)
Lymph Node, Bronchial | (7) | (6) | (4) | (6) | (7) | (9)
Foreign Body | – | – | – | 4 (67%) | 7 (100%) | 9 (100%)
Hyperplasia, Lymphoid | – | 1 (17%) | – | 2 (33%) | 6 (86%) | 7 (78%)
Lymph Node, Mediastinal | (10) | (10) | (9) | (10) | (10) | (10)
Foreign Body | – | 1 (10%) | 1 (11%) | 6 (60%) | 10 (100%) | 10 (100%)
Hyperplasia, Lymphoid | 2 (20%) | 3 (30%) | 3 (33%) | 7 (70%) | 9 (90%) | 10 (100%)
Pigmentation | 1 (10%) | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Larynx | (10) | (10) | (10) | (10) | (10) | (10)
Epiglottis, Metaplasia, Squamous | – | 1 (10%) | – | 6 (60%) | 9 (90%) | 7 (70%)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Foreign Body | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Inflammation, Chronic | – | 3 (30%) | 2 (20%) | 6 (60%) | 10 (100%) | 10 (100%)
Alveolar Epithelium, Hyperplasia | – | – | – | 2 (20%) | 10 (100%) | 10 (100%)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 1 (10%) | – | 1 (10%) | 1 (10%) | – | 4 (40%)
Respiratory Epithelium, Accumulation, Hyaline Droplet | – | – | – | – | – | 1 (10%)
Trachea | (8) | (10) | (10) | (10) | (10) | (10)
Special Senses System
None | – | – | – | – | – | –
Urinary System
None | – | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m^3^ | 10 mg/m^3^
Disposition Summary
Animals Initially in Study | 35 | 35 | 35 | 35 | 35 | 35
Survivors
Terminal Euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Lung Burden Study | 25 | 25 | 25 | 25 | 25 | 25
Animals Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Pharynx | (10) | (10) | (10) | (10) | (10) | (10)
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
Lymph Node | (0) | (1) | (0) | (0) | (0) | (0)
Lumbar, Hyperplasia, Lymphoid | – | 1 (100%) | – | – | – | –
Lumbar, Pigmentation | – | 1 (100%) | – | – | – | –
Lymph Node, Bronchial | (6) | (9) | (7) | (7) | (9) | (7)
Foreign Body | – | – | – | 5 (71%) | 9 (100%) | 6 (86%)
Hyperplasia, Lymphoid | – | – | – | 2 (29%) | 5 (56%) | 3 (43%)
Lymph Node, Mediastinal | (9) | (7) | (8) | (10) | (9) | (9)
Foreign Body | – | – | 1 (13%) | 2 (20%) | 1 (11%) | 3 (33%)
Hyperplasia, Lymphoid | – | – | – | 1 (10%) | 1 (11%) | 3 (33%)
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Larynx | (9) | (10) | (10) | (10) | (10) | (10)
Epiglottis, Metaplasia, Squamous | 1 (11%) | 2 (20%) | 3 (30%) | 6 (60%) | 9 (90%) | 10 (100%)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Foreign Body | – | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Inflammation, Chronic | – | – | – | 8 (80%) | 10 (100%) | 10 (100%)
Alveolus, Proteinosis | – | – | – | – | 3 (30%) | 10 (100%)
Bronchiole, Epithelium, Hyperplasia | – | – | – | – | 7 (70%) | 10 (100%)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, Suppurative | 1 (10%) | – | – | – | – | –
Olfactory Epithelium, Accumulation, Hyaline Droplet | – | – | – | – | 2 (20%) | 9 (90%)
Respiratory Epithelium, Accumulation, Hyaline Droplet | – | – | – | 3 (30%) | 9 (90%) | 10 (100%)
Trachea | (10) | (10) | (10) | (8) | (10) | (10)
Special Senses System
None | – | – | – | – | – | –
Urinary System
None | – | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the 30-day Inhalation Study of 1020 Long Multiwalled Carbon Nanotubes^a^

| Chamber Control | 0.1 mg/m^3^ | 0.3 mg/m^3^ | 1 mg/m^3^ | 3 mg/m3 | 10 mg/m^3^
Disposition Summary
Animals Initially in Study | 35 | 35 | 35 | 35 | 35 | 35
Survivors
Terminal Euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Lung Burden Study | 25 | 25 | 25 | 25 | 25 | 25
Animals Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (2) | (0) | (0) | (0) | (0) | (0)
Necrosis, Focal | 1 (50%) | – | – | – | – | –
Pharynx | (10) | (10) | (10) | (10) | (10) | (10)
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
Lymph Node | (1) | (1) | (2) | (0) | (1) | (1)
Lumbar, Pigmentation | 1 (100%) | 1 (100%) | 2 (100%) | – | 1 (100%) | 1 (100%)
Lymph Node, Bronchial | (9) | (3) | (8) | (9) | (6) | (6)
Foreign Body | – | – | – | 3 (33%) | 5 (83%) | 5 (83%)
Hyperplasia, Lymphoid | 1 (11%) | – | – | 2 (22%) | 3 (50%) | 5 (83%)
Lymph Node, Mediastinal | (7) | (8) | (8) | (7) | (10) | (9)
Foreign Body | – | – | – | – | 4 (40%) | 7 (78%)
Hyperplasia, Lymphoid | – | – | – | 1 (14%) | 1 (10%) | 5 (56%)
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Larynx | (10) | (10) | (10) | (10) | (10) | (10)
Epiglottis, Metaplasia, Squamous | 1 (10%) | 1 (10%) | 1 (10%) | 4 (40%) | 6 (60%) | 10 (100%)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Foreign Body | – | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Inflammation, Chronic | – | – | – | 4 (40%) | 10 (100%) | 10 (100%)
Metaplasia, Osseous | – | 1 (10%) | – | – | – | –
Alveolus, Proteinosis | – | – | – | – | 9 (90%) | 10 (100%)
Bronchiole, Epithelium, Hyperplasia | – | – | – | – | 6 (60%) | 10 (100%)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory Epithelium, Accumulation, Hyaline Droplet | – | – | 1 (10%) | 3 (30%) | 8 (80%) | 10 (100%)
Respiratory Epithelium, Accumulation, Hyaline Droplet | – | – | – | 8 (80%) | 10 (100%) | 10 (100%)
Trachea | (10) | (9) | (10) | (10) | (9) | (10)
Special Senses System
None | – | – | – | – | – | –
Urinary System
None | – | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.