# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-93

Report Series: NTP Toxicity Report Series

Report Series Number: 93

Official citation: National Toxicology Program (NTP). 2017. NTP technical report on the toxicity study of chitosan (CASRN 9012-76-4) administered in feed to Sprague Dawley [Crl:CD(SD)] rats. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 93.