# Peer Review

The draft NTP Technical Report on the Toxicity Study of Chitosan (CASRN 9012-76-4) Administered in Feed to Sprague Dawley [Crl:CD(SD)] Rats was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of this NTP study were appropriate and ensured that this Toxicity Study Report presents the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Diane Birt, Ph.D.
  Iowa State University (Retired)
  Ames, Iowa, USA
- Melissa G. Rhodes, Ph.D.
  Roivant Sciences, Inc.
  Durham, North Carolina, USA