# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  K.A. Shipkowski, Ph.D., Co-Study Scientist
  B.C. Sayers, Ph.D., Co-Study Scientist
  S.A. Elmore, D.V.M., Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted study and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  L.M. Fomby, D.V.M., Ph.D.
  T.A. Peace, D.V.M.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Peer Review (December 19, 2008)
  J.T. Painter, D.V.M., Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Provided sperm parameter data
  R.W. Tyl, Ph.D., Principal Investigator