# References

1 Kean T, Thanou M. Biodegradation, biodistribution and toxicity of chitosan. Adv Drug Del Rev. 2010; 62(1):3-11. http://dx.doi.org/10.1016/j.addr.2009.09.004
2 Rinaudo M Chitin and chitosan: properties and applications. Prog Polym Sci. 2006; 31(7):603–632.http://dx.doi.org/10.1016/j.progpolymsci.2006.06.001
3 Kubota N Eguchi Y Facile preparation of water-soluble N-acetylated chitosan and molecular weight dependence of its water-solubility. Polym J. 1997; 29(2):123.http://dx.doi.org/10.1295/polymj.29.123
4 Peniston Q, Johnson E. inventors. Process for the manufacture of chitosan. United States patent 4,195,175; 1980.
5 Hirano S Chitin biotechnology applications. Biotechnol Annu Rev. 1996; 2:237–258. http://dx.doi.org/10.1016/S1387-2656(08)70012-7 9704098
6 Wedmore I McManus JG Pusateri AE Holcomb JB A special report on the chitosan-based hemostatic dressing: experience in current combat operations. J Trauma. 2006; 60(3):655–658. http://dx.doi.org/10.1097/01.ta.0000199392.91772.44 16531872
7 Songjiang Z Lixiang W Amyloid-beta associated with chitosan nano-carrier has favorable immunogenicity and permeates the BBB. AAPS PharmSciTech. 2009; 10(3):900–905. http://dx.doi.org/10.1208/s12249-009-9279-1 19609682
8 Felt O Buri P Gurny R Chitosan: a unique polysaccharide for drug delivery. Drug Dev Ind Pharm. 1998; 24(11):979–993. http://dx.doi.org/10.3109/03639049809089942 9876553
9 Lang G, Wendel H, Konrad E. inventors. Cosmetics composition based upon chitosan derivatives, new chitosan derivatives as well as processes for production thereof. United States patent 4,528,283; 1985.
10 Carvalho TS Lussi A Combined effect of a fluoride-, stannous- and chitosan-containing toothpaste and stannous-containing rinse on the prevention of initial enamel erosion-abrasion. J Dent. 2014; 42(4):450–459. http://dx.doi.org/10.1016/j.jdent.2014.01.004 24440712
11 Ebihara K Schneeman BO Interaction of bile acids, phospholipids, cholesterol and triglyceride with dietary fibers in the small intestine of rats. J Nutr. 1989; 119(8):1100–1106. http://dx.doi.org/10.1093/jn/119.8.1100 2550597
12 Gallaher CM Munion J Hesslink R Jr Wise J Gallaher DD Cholesterol reduction by glucomannan and chitosan is mediated by changes in cholesterol absorption and bile acid and fat excretion in rats. J Nutr. 2000; 130(11):2753–2759. http://dx.doi.org/10.1093/jn/130.11.2753 11053517
13 Liu J Zhang J Xia W Hypocholesterolaemic effects of different chitosan samples in vitro and in vivo. Food Chem. 2008; 107(1):419–425.http://dx.doi.org/10.1016/j.foodchem.2007.08.044
14 Ikeda I Sugano M Yoshida K Sasaki E Iwamoto Y Hatano K Effects of chitosan hydrolyzates on lipid absorption and on serum and liver lipid concentration in rats. J Agric Food Chem. 1993; 41(3):431–435.http://dx.doi.org/10.1021/jf00027a016
15 Kanauchi O Deuchi K Imasato Y Shizukuishi M Kobayashi E Mechanism for the inhibition of fat digestion by chitosan and for the synergistic effect of ascorbate. Biosci Biotechnol Biochem. 1995; 59(5):786–790. http://dx.doi.org/10.1271/bbb.59.786 7787293
16 General Nutrition Centers Inc GNC Total LeanTM chitosan with glucomannan. 2015. https://www.gnc.com/GNC-Total-Lean-Chitosan-with-Glucomannan/product.jsp?productId=2459379 [Accessed: June, 2016]
17 Vitamin World Inc Chitosan 500 mg. 2015. https://www.vitaminworld.com/fiber/chitosan-500mg-0070004945.html [Accessed: June, 2016]
18 Chae SY Jang M-K Nah J-W Influence of molecular weight on oral absorption of water soluble chitosans. J Control Release. 2005; 102(2):383–394. http://dx.doi.org/10.1016/j.jconrel.2004.10.012 15653159
19 Yang YM Hu W Wang XD Gu XS The controlling biodegradation of chitosan fibers by N-acetylation in vitro and in vivo. J Mater Sci Mater Med. 2007; 18(11):2117–2121. http://dx.doi.org/10.1007/s10856-007-3013-x 17619982
20 Funkhouser JD Aronson NN Jr Chitinase family GH18: evolutionary insights from the genomic history of a diverse protein family. BMC Evol Biol. 2007; 7(1):96. http://dx.doi.org/10.1186/1471-2148-7-96 17594485
21 Qin C Gao J Wang L Zeng L Liu Y Safety evaluation of short-term exposure to chitooligomers from enzymic preparation. Food Chem Toxicol. 2006; 44(6):855–861. http://dx.doi.org/10.1016/j.fct.2005.11.009 16442198
22 Vahouny GV Satchithanandam S Cassidy MM Lightfoot FB Furda I Comparative effects of chitosan and cholestyramine on lymphatic absorption of lipids in the rat. Am J Clin Nutr. 1983; 38(2):278–284. http://dx.doi.org/10.1093/ajcn/38.2.278 6881083
23 Fukada Y Kimura K Ayaki Y Effect of chitosan feeding on intestinal bile acid metabolism in rats. Lipids. 1991; 26(5):395–399. 10.1007/BF02537206 1895888
24 Landes DR Bough WA Effects of chitosan—a coagulating agent for food processing wastes—in the diets of rats on growth and liver and blood composition. Bull Environ Contam Toxicol. 1976;15(5):555–563. http://dx.doi.org/10.1007/BF01685704 1268362
25 Tanaka Y Tanioka S Tanaka M Tanigawa T Kitamura Y Minami S Okamoto Y Miyashita M Nanno M Effects of chitin and chitosan particles on BALB/c mice by oral and parenteral administration. Biomaterials. 1997; 18(8):591–595. http://dx.doi.org/10.1016/S0142-9612(96)00182-2 9134158
26 Deuchi K Kanauchi O Shizukuishi M Kobayashi E Continuous and massive intake of chitosan affects mineral and fat-soluble vitamin status in rats fed on a high-fat diet. Biosci Biotechnol Biochem. 1995; 59(7):1211–1216. http://dx.doi.org/10.1271/bbb.59.1211 7670180
27 Fukui K Nakamura K Shirai M Hirano A Takatsu H Urano S Long-term vitamin E-deficient mice exhibit cognitive dysfunction via elevation of brain oxidation. J Nutr Sci Vitaminol (Tokyo). 2015; 61(5):362–368. http://dx.doi.org/10.3177/jnsv.61.362 26639843
28 Oliveros LB Domeniconi MA Vega VA Gatica LV Brigada AM Gimenez MS Vitamin A deficiency modifies lipid metabolism in rat liver. Br J Nutr. 2007; 97(2):263–272. http://dx.doi.org/10.1017/S0007114507182659 17298694
29 Naito Y Tago K Nagata T Furuya M Seki T Kato H Morimura T Ohara N A 90-day ad libitum administration toxicity study of oligoglucosamine in F344 rats. Food Chem Toxicol. 2007; 45(9):1575–1587. http://dx.doi.org/10.1016/j.fct.2007.02.018 17418928
30 Hirano S Iwata M Yamanaka K Tanaka H Toda T Inui H Enhancement of serum lysozyme activity by injecting a mixture of chitosan oligosaccharides intravenously in rabbits. Agric Biol Chem. 1991; 55(10):2623–2625.https://doi.org/10.1080/00021369.1991.10871007
31 Rao SB, Sharma CP. Use of chitosan as a biomaterial: Studies on its safety and hemostatic potential. J Biomed Mater Res. 1997; 34(1):21-28. http://dx.doi.org/10.1002/(SICI)1097-4636(199701)34:1<21::AID-JBM4>3.0.CO;2-P
32 Gades MD Stern JS Chitosan supplementation and fecal fat excretion in men. Obes Res. 2003;11(5):683–688. http://dx.doi.org/10.1038/oby.2003.97 12740459
33 Gades MD Stern JS Chitosan supplementation and fat absorption in men and women. J Am Diet Assoc. 2005; 105(1):72–77. http://dx.doi.org/10.1016/j.jada.2004.10.004 15635349
34 Tapola NS Lyyra ML Kolehmainen RM Sarkkinen ES Schauss AG Safety aspects and cholesterol-lowering efficacy of chitosan tablets. J Am Coll Nutr. 2008; 27(1):22–30. http://dx.doi.org/10.1080/07315724.2008.10719671 18460478
35 Takahashi M Inoue K Yoshida M Morikawa T Shibutani M Nishikawa A Lack of chronic toxicity or carcinogenicity of dietary N-acetylglucosamine in F344 rats. Food Chem Toxicol. 2009; 47(2):462–471. http://dx.doi.org/10.1016/j.fct.2008.12.002 19103248
36 Cheng Q Zhang J Xia W Prenatal and developmental effect of high molecular weight chitosan (HMWCS) to mice. Regul Toxicol Pharmacol. 2013; 65(3):294–303. http://dx.doi.org/10.1016/j.yrtph.2013.01.003 23321397
37 Hu Y-L Qi W Han F Shao J-Z Gao J-Q Toxicity evaluation of biodegradable chitosan nanoparticles using a zebrafish embryo model. Int J Nanomedicine. 2011; 6:3351–3359. 22267920
38 Domard A Rinaudo M Preparation and characterization of fully deacetylated chitosan. Int J Biol Macromol. 1983; 5(1):49–52.http://dx.doi.org/10.1016/0141-8130(83)90078-8
39 Hirai A Odani H Nakajima A Determination of degree of deacetylation of chitosan by 1 H NMR spectroscopy. Polym Bull. 1991; 26(1):87–94.http://dx.doi.org/10.1007/BF00299352
40 Rao GN New nonpurified diet (NTP-2000) for rodents in the National Toxicology Program’s toxicology and carcinogenesis studies. J Nutr. 1997; 127(5) Suppl:842S–846S. http://dx.doi.org/10.1093/jn/127.5.842S 9164250
41 Reeves PG Components of the AIN-93 diets as improvements in the AIN-76A diet. J Nutr. 1997; 127(5) Suppl:838S–841S. http://dx.doi.org/10.1093/jn/127.5.838S 9164249
42 Reeves PG Nielsen FH Fahey GC Jr AIN-93 purified diets for laboratory rodents: final report of the American Institute of Nutrition ad hoc writing committee on the reformulation of the AIN-76A rodent diet. J Nutr. 1993; 123(11):1939–1951. http://dx.doi.org/10.1093/jn/123.11.1939 8229312
43 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
44 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
45 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
46 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.http://dx.doi.org/10.1080/01621459.1955.10501294
47 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
48 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
49 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
50 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
51 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
52 Jonckheere A A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41:133–145.http://dx.doi.org/10.1093/biomet/41.1-2.133
53 Dixon W Massey F Introduction to statistical analysis. New York (NY): McGraw Hill Book Company Inc; 1957. 10.2307/2332898
54 Code of Federal Regulations (CFR). 21:Part 58.
55 Deuchi K Kanauchi O Imasato Y Kobayashi E Effect of the viscosity or deacetylation degree of chitosan on fecal fat excreted from rats fed on a high-fat diet. Biosci Biotechnol Biochem. 1995; 59(5):781–785. http://dx.doi.org/10.1271/bbb.59.781 7787292
56 Chiang M-T Yao H-T Chen H-C Effect of dietary chitosans with different viscosity on plasma lipids and lipid peroxidation in rats fed on a diet enriched with cholesterol. Biosci Biotechnol Biochem. 2000; 64(5):965–971. http://dx.doi.org/10.1271/bbb.64.965 10879465
57 Hossain S Rahman A Kabir Y Shams AA Afros F Hashimoto M Effects of shrimp (Macrobracium rosenbergii)-derived chitosan on plasma lipid profile and liver lipid peroxide levels in normo- and hypercholesterolaemic rats. Clin Exp Pharmacol Physiol. 2007; 34(3):170–176. http://dx.doi.org/10.1111/j.1440-1681.2007.04568.x 17250635
58 Sugano M Fujikawa T Hiratsuji Y Hasegawa Y Hypocholesterolemic effects of chitosan in cholesterol-fed rats. Nutr Rep Int. 1978; 18:531–537.
59 Sugano M Fujikawa T Hiratsuji Y Nakashima K Fukuda N Hasegawa Y A novel use of chitosan as a hypocholesterolemic agent in rats. Am J Clin Nutr. 1980; 33(4):787–793. http://dx.doi.org/10.1093/ajcn/33.4.787 7361697
60 Rucker R Morris J Fascetti A Vitamins. In: Kaneko J Harvey J Bruss Meditors. Clinical biochemistry of domestic animals. Burlington (MA): Academic Press; 2008. p. 695–730. 10.1016/B978-0-12-370491-7.00023-4
61 Sommer A Vitamin a deficiency and clinical disease: an historical overview. J Nutr. 2008; 138(10):1835–1839. http://dx.doi.org/10.1093/jn/138.10.1835 18806089
62 Traber MG Vitamin E inadequacy in humans: causes and consequences. Adv Nutr. 2014; 5(5):503–514. http://dx.doi.org/10.3945/an.114.006254 25469382
63 Wiseman EM Bar-El Dadon S Reifen R The vicious cycle of vitamin a deficiency: A review. Crit Rev Food Sci Nutr. 2017; 57(17):3703–3714. http://dx.doi.org/10.1080/10408398.2016.1160362 27128154
64 Yang C-Y Oh T-W Nakajima D Maeda A Naka T Kim C-S Igawa S Ohta F Effects of habitual chitosan intake on bone mass, bone-related metabolic markers and duodenum CaBP D9K mRNA in ovariectomized SHRSP rats. J Nutr Sci Vitaminol (Tokyo). 2002; 48(5):371–378. http://dx.doi.org/10.3177/jnsv.48.371 12656210
65 Wada M Nishimura Y Watanabe Y Takita T Innami S Accelerating effect of chitosan intake on urinary calcium excretion by rats. Biosci Biotechnol Biochem. 1997; 61(7):1206–1208. http://dx.doi.org/10.1271/bbb.61.1206 9255987
66 Tieder M Arie R Modai D Samuel R Weissgarten J Liberman UA Elevated serum 1,25-dihydroxyvitamin D concentrations in siblings with primary Fanconi’s syndrome. N Engl J Med. 1988; 319(13):845–849. http://dx.doi.org/10.1056/NEJM198809293191307 2842681
67 Thoolen B, Maronpot RR, Harada T, Nyska A, Rousseaux C, Nolte T, Malarkey DE, Kaufmann W, Küttler K, Deschl U, et al. Proliferative and nonproliferative lesions of the rat and mouse hepatobiliary system. Toxicol Pathol. 2010; 38(7_suppl):5S-81S. http://dx.doi.org/10.1177/0192623310386499
68 Hassan K Bhalla V El Regal ME A-Kader HH Nonalcoholic fatty liver disease: a comprehensive review of a growing epidemic. World J Gastroenterol. 2014; 20(34):12082–12101. http://dx.doi.org/10.3748/wjg.v20.i34.12082 25232245
69 Sozio MS Liangpunsakul S Crabb D The role of lipid metabolism in the pathogenesis of alcoholic and nonalcoholic hepatic steatosis. Semin Liver Dis. 2010; 30(4):378–390. http://dx.doi.org/10.1055/s-0030-1267538 20960377
70 Greaves P Liver and pancreas. In: Greaves Peditor. Histopatology of Preclinical Toxicity Studies. 3rd ed. Oxford, UK: Elsevier; 2007. p. 457–569.http://dx.doi.org/10.1016/B978-044452771-4/50010-9
71 Singh VN Singh M Venkitasubramanian TA Early effects of feeding excess vitamin A: mechanism of fatty liver production in rats. J Lipid Res. 1969; 10(4):395–401. 5797525
72 Kucera O Cervinkova Z Experimental models of non-alcoholic fatty liver disease in rats. World J Gastroenterol. 2014; 20(26):8364–8376. http://dx.doi.org/10.3748/wjg.v20.i26.8364 25024595
73 Jungermann K Katz N Functional specialization of different hepatocyte populations. Physiol Rev. 1989; 69(3):708–764. http://dx.doi.org/10.1152/physrev.1989.69.3.708 2664826
74 Pearse G Histopathology of the thymus. Toxicol Pathol. 2006; 34(5):515–547. http://dx.doi.org/10.1080/01926230600978458 17067942
75 Lelovas PP Xanthos TT Thoma SE Lyritis GP Dontas IA The laboratory rat as an animal model for osteoporosis research. Comp Med. 2008; 58(5):424–430. 19004367
76 Wronski TJ Dann LM Scott KS Cintrón M Long-term effects of ovariectomy and aging on the rat skeleton. Calcif Tissue Int. 1989; 45(6):360–366. http://dx.doi.org/10.1007/BF02556007 2509027
77 Fukuda S Iida H Age-related changes in bone mineral density, cross-sectional area and the strength of long bones in the hind limbs and first lumbar vertebra in female Wistar rats. J Vet Med Sci. 2004; 66(7):755–760. 10.1292/jvms.66.755 15297744