# Results

## Six-month Study

All male and female Group A rats survived to the end of the study (Table 3); however, five rats from Groups B and C died, often after seizures that occurred near the time of blood collection, with the cause of death undetermined. There were no treatment-related clinical findings in Group A animals, although 13 animals from Groups B and C (10 from the 9% group, one from the 3% group, and two from the 1% group) were observed with seizures either during or after the 18-week blood collections. Seizures were not noted at any other time point. Body weights and feed consumption were measured in Group A rats, and mean body weights of exposed males and females were not significantly different from those of the control groups (Table 3 and Figure 2). Feed consumption by 3% and 9% Group A males was greater than that by the controls, but the increase may not be accurate due to observed food spillage possibly due to poor palatability resulting in feed being wasted (Table G-1). Dietary concentrations of 1%, 3%, and 9% resulted in average daily doses of approximately 450, 1,500, and 5,200 mg chitosan/kg body weight per day to males and 650, 1,800, and 6,000 mg/kg per day to females, respectively.

Table 3 Survival, Body Weights, and Feed Consumption of Group A Rats in the Six-month Feed Study of Chitosan^a^

Concentration | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Feed Consumption Week 1 | Feed Consumption Week 25
Male
0% | 10/10 | 238 ± 5 | 669 ± 20 | 432 ± 18 | | 22.2 | 21.2
1% | 10/10 | 243 ± 6 | 702 ± 21 | 459 ± 17 | 105 | 23.8 | 20.4
3% | 10/10 | 242 ± 6 | 687 ± 23 | 445 ± 21 | 103 | 23.6 | 24.7
9% | 10/10 | 243 ± 6 | 612 ± 17 | 369 ± 17 | 91 | 21.4 | 27.3
Female
0% | 10/10 | 175 ± 3 | 338 ± 11 | 162 ± 12 | | 17.7 | 16.4
1% | 10/10 | 173 ± 2 | 335 ± 13 | 162 ± 12 | 99 | 22.3 | 20.3
3% | 10/10 | 177 ± 4 | 328 ± 11 | 151 ± 9 | 97 | 17.3 | 17.1
9% | 10/10 | 177 ± 2 | 301 ± 13 | 124 ± 12 | 89 | 16.9 | 18.8

^a^ Weights and weight changes are given as mean ± standard error. Feed consumption is expressed as grams per animal per day. Differences in weights and weight changes from the control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 25 weeks/number initially in group.

Figure 2

Growth Curves for Group A Rats Exposed to Chitosan in Feed for Six Months

Hematology data for Group C rats are listed in Table B-1. Compared to the control group, mild significant increases (4% to 6%) in automated hematocrit, hemoglobin concentration, mean cell volume, and mean cell hemoglobin were observed in 9% males; manual hematocrit and erythrocyte count were similar to those of the controls. These changes may be due to biological variability and are likely not toxicologically relevant. All other differences from control values in the male and female hematology data were mild or sporadic and not considered toxicologically significant.

Clinical chemistry data for Group C rats are listed in Table 4 and Table B-1. Both the 9% male and female rats had significantly decreased cholesterol values (26% to 48%), compared to the controls, at all time points. Triglycerides values were also significantly decreased in the 9% male (47% to 57%) and female (30%) rats, but not at every time point. Phosphorus levels were significantly decreased in the 9% male rats at weeks 13, 19, and 25 (12% to 18%); a decrease also occurred in the 3% males at week 13 (14%). Similarly, phosphorus levels were significantly decreased in the 3% and 9% females at weeks 13 (20% and 16%, respectively) and 25 (9% and 19%, respectively). A mild, but statistically significant, decrease (4%) in calcium concentration was observed in 9% males at weeks 19 and 25. Alanine aminotransferase (ALT) activity, a marker of hepatocellular injury, was mildly but significantly elevated at week 25 in the 9% male rats (104%) and in the 3% and 9% female rats (28% and 88%, respectively). However, sorbitol dehydrogenase (another marker of hepatocellular injury) was not significantly increased relative to the controls, and hepatocellular changes associated with increases in ALT were not observed microscopically. Thus, the toxicologic significance of the increases in ALT is uncertain. Urea nitrogen was mildly increased in the 9% males (23%) and females (15%) at week 25. Minimal to mild significant alterations were also observed in several other parameters. These alterations were inconsistent or within the range of biological variability.

Table 4 Selected Clinical Chemistry and Urinalysis Data for Group C Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
Male
Clinical Chemistry
n | 10 | 10 | 10 | 10
Calcium (mg/dL)
Week 13 | 12.6 ± 0.1 | 12.5 ± 0.1 | 12.3 ± 0.2 | 12.4 ± 0.2
Week 19 | 12.5 ± 0.1 | 12.3 ± 0.2 | 12.3 ± 0.1 | 12.0 ± 0.1*
Week 25 | 12.1 ± 0.1 | 12.1 ± 0.2 | 12.0 ± 0.1 | 11.6 ± 0.1*
Phosphorus (mg/dL)
Week 13 | 8.4 ± 0.3 | 8.1 ± 0.3 | 7.2 ± 0.3** | 7.4 ± 0.4*
Week 19 | 8.2 ± 0.4 | 7.7 ± 0.2 | 7.4 ± 0.3 | 6.7 ± 0.2**
Week 25 | 6.9 ± 0.3 | 6.8 ± 0.2 | 6.7 ± 0.1 | 5.8 ± 0.3**
Cholesterol (mg/dL)
Week 7 | 82 ± 5 | 75 ± 8 | 80 ± 6 | 53 ± 3**
Week 13 | 95 ± 7 | 84 ± 8 | 90 ± 7 | 53 ± 2**
Week 19 | 101 ± 6 | 87 ± 10 | 94 ± 8 | 59 ± 4**
Week 25 | 95 ± 6 | 81 ± 8 | 90 ± 6 | 49 ± 4**
Triglycerides (mg/dL)
Week 7 | 202 ± 28 | 234 ± 43 | 226 ± 30 | 88 ± 15*
Week 13 | 198 ± 33 | 202 ± 38 | 195 ± 24 | 86 ± 8**
Week 19 | 180 ± 26 | 218 ± 43 | 210 ± 29 | 95 ± 13*
Week 25 | 173 ± 18 | 207 ± 30 | 218 ± 24 | 109 ± 13
Alanine aminotransferase (IU/L)
Week 25 | 28 ± 3 | 29 ± 2 | 29 ± 1 | 57 ± 2**
Sorbitol dehydrogenase (IU/L)
Week 25 | 17 ± 3 | 17 ± 2 | 15 ± 1 | 14 ± 1
Total osteocalcin (ng/mL)
Week 7 | 445.7 ± 17.2 | 439.8 ± 15.8 | 441.8 ± 18.2 | 520.4 ± 22.6
Week 13 | 306.2 ± 13.0 | 289.7 ± 28.6 | 245.4 ± 37.9 | 372.6 ± 23.4
Week 19 | 239.4 ± 12.4 | 225.7 ± 10.6 | 181.6 ± 26.8 | 269.2 ± 20.9
Week 25 | 158.3 ± 10.0 | 168.1 ± 11.6 | 145.9 ± 22.7 | 218.3 ± 14.6*
Parathyroid hormone (ng/mL)
Week 7 | 1.882 ± 0.137 | 1.643 ± 0.449 | 1.838 ± 0.348 | 1.521 ± 0.368
Week 13 | 2.343 ± 0.350 | 2.763 ± 0.479 | 3.215 ± 0.537 | 2.433 ± 0.222
Week 19 | 1.879 ± 0.186 | 3.101 ± 0.475 | 2.710 ± 0.365 | 3.679 ± 0.361**
Week 25 | 2.668 ± 0.475 | 2.924 ± 0.276 | 3.981 ± 0.349 | 2.848 ± 0.506
Urinalysis
n
Week 7 | 10 | 9 | 10 | 10
Week 13 | 10 | 10 | 10 | 10
Week 19 | 10 | 10 | 10 | 10
Week 25 | 10 | 10 | 10 | 10
Volume (mL)
Week 7 | 8.3 ± 0.8 | 7.5 ± 1.5 | 6.4 ± 0.8 | 5.0 ± 1.1*
Week 13 | 7.9 ± 1.0 | 4.6 ± 0.3** | 5.1 ± 0.4* | 4.5 ± 0.5**
Week 19 | 10.7 ± 1.6 | 4.0 ± 0.4** | 5.3 ± 0.7* | 5.6 ± 0.6
Week 25 | 8.6 ± 1.2 | 5.4 ± 0.6* | 6.1 ± 0.8* | 5.1 ± 0.6**
Deoxypyridinoline/creatinine (nmol/mg)
Week 7 | 1.810 ± 0.135 | 1.889 ± 0.148 | 1.810 ± 0.159 | 1.920 ± 0.160
Week 13 | 0.910 ± 0.035 | 0.890 ± 0.031 | 0.930 ± 0.040 | 0.960 ± 0.078
Week 19 | 0.530 ± 0.050 | 0.550 ± 0.034 | 0.570 ± 0.042 | 0.660 ± 0.048
Week 25 | 0.430 ± 0.030 | 0.470 ± 0.030 | 0.480 ± 0.020 | 0.550 ± 0.027**
Female
Clinical Chemistry
n
Week 7 | 10 | 10 | 10 | 10
Week 13 | 10 | 10 | 10 | 10
Week 19 | 10 | 10 | 10 | 10
Week 25 | 10 | 9 | 10 | 10
Calcium (mg/dL)
Week 13 | 12.9 ± 0.2 | 13.1 ± 0.1 | 12.7 ± 0.2 | 12.5 ± 0.2
Week 19 | 12.9 ± 0.1 | 13.1 ± 0.2 | 12.8 ± 0.1 | 12.5 ± 0.1
Week 25 | 12.7 ± 0.3 | 12.8 ± 0.1 | 12.7 ± 0.2 | 12.3 ± 0.2
Phosphorus (mg/dL)
Week 13 | 8.1 ± 0.5 | 7.4 ± 0.4 | 6.5 ± 0.4** | 6.8 ± 0.3*
Week 19 | 8.4 ± 0.4 | 8.2 ± 0.5 | 8.1 ± 0.3 | 7.4 ± 0.5
Week 25 | 6.8 ± 0.2 | 6.4 ± 0.2 | 6.2 ± 0.3* | 5.5 ± 0.3**
Cholesterol (mg/dL)
Week 7 | 80 ± 6 | 81 ± 8 | 67 ± 4 | 59 ± 4**
Week 13 | 92 ± 8 | 86 ± 7 | 73 ± 5 | 58 ± 4**
Week 19 | 107 ± 7 | 105 ± 9 | 91 ± 8 | 67 ± 5**
Week 25 | 94 ± 7 | 108 ± 5 | 96 ± 8 | 63 ± 4**
Triglycerides (mg/dL)
Week 7 | 88 ± 12 | 130 ± 48 | 81 ± 8 | 86 ± 14
Week 13 | 125 ± 10 | 163 ± 30 | 140 ± 23 | 88 ± 23*
Week 19 | 143 ± 15 | 181 ± 32 | 137 ± 18 | 90 ± 13
Week 25 | 188 ± 31 | 231 ± 44 | 245 ± 31 | 158 ± 35
Alanine aminotransferase (IU/L)
Week 25 | 25 ± 3 | 28 ± 3 | 32 ± 2** | 47 ± 4**
Sorbitol dehydrogenase (IU/L)
Week 25 | 17 ± 3 | 17 ± 2 | 19 ± 2 | 16 ± 1
Total osteocalcin (ng/mL)
Week 7 | 293.6 ± 19.4 | 287.5 ± 21.2 | 282.1 ± 34.7 | 316.7 ± 23.5
Week 13 | 197.9 ± 22.6 | 202.3 ± 15.4 | 184.4 ± 19.4 | 234.2 ± 14.5
Week 19 | 158.1 ± 18.3 | 184.8 ± 13.2 | 166.7 ± 24.7 | 210.1 ± 16.0
Week 25 | 107.9 ± 18.6 | 97.1 ± 7.1 | 96.0 ± 16.2 | 148.8 ± 15.1
Parathyroid hormone (ng/mL)
Week 7 | 0.995 ± 0.150^b^ | 1.156 ± 0.176 | 1.092 ± 0.182 | 1.023 ± 0.146
Week 13 | 1.506 ± 0.203 | 1.734 ± 0.194 | 1.925 ± 0.306 | 1.767 ± 0.212
Week 19 | 1.406 ± 0.232 | 1.994 ± 0.353 | 1.845 ± 0.418 | 1.673 ± 0.223
Week 25 | 1.471 ± 0.189^b^ | 1.628 ± 0.220 | 1.818 ± 0.224 | 2.301 ± 0.212*
Urinalysis
n
Week 7 | 10 | 10 | 10 | 10
Week 13 | 10 | 10 | 10 | 10
Week 19 | 10 | 10 | 10 | 10
Week 25 | 10 | 9 | 10 | 9
Volume (mL)
Week 7 | 8.2 ± 1.2 | 8.5 ± 1.0 | 5.4 ± 0.8 | 3.4 ± 0.3**
Week 13 | 6.4 ± 0.7 | 6.5 ± 0.6 | 4.1 ± 0.8* | 2.9 ± 0.5**
Week 19 | 7.7 ± 1.2 | 8.1 ± 1.4 | 5.0 ± 0.8 | 3.4 ± 0.5**
Week 25 | 8.2 ± 1.5 | 9.1 ± 1.5 | 5.8 ± 0.9 | 3.7 ± 0.5**
Deoxypyridinoline/creatinine (nmol/mg)
Week 7 | 1.620 ± 0.128 | 1.240 ± 0.129 | 1.940 ± 0.229 | 2.300 ± 0.182*
Week 13 | 0.580 ± 0.039 | 0.430 ± 0.037** | 0.540 ± 0.034 | 0.570 ± 0.042
Week 19 | 0.450 ± 0.017 | 0.360 ± 0.016* | 0.440 ± 0.016 | 0.520 ± 0.020
Week 25 | 0.340 ± 0.043 | 0.222 ± 0.022 | 0.340 ± 0.027 | 0.411 ± 0.026

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

Total osteocalcin (a marker of bone turnover) and parathyroid hormone levels were analyzed in Group C rats and were occasionally elevated throughout the study. Total osteocalcin was significantly elevated in the 9% males (38%) at week 25, while parathyroid hormone levels were significantly elevated in 9% males (96%) at Week 19 and in 9% females (56%) at week 25 (Table 4 and Table B-1).

Urine deoxypyridinoline/creatinine ratios were calculated at weeks 7, 13, 19, and 25 for both males and females in Group C and were mostly unchanged (Table 4 and Table B-1). A significant increase, compared to the control group, occurred at week 25 in the 9% males (28%). In females, minimal increases and decreases occurred inconsistently across all time points with a significant increase at week 7 in the 9% group (42%) and significant decreases at weeks 13 (26%) and 19 (20%) in the 1% group compared to controls.

To calculate the deoxypyridinoline/creatinine ratios, urine volume, urine creatinine concentrations, and urine deoxypyridinoline concentrations were measured at weeks 7, 13, 19, and 25. Urine volume was significantly decreased in various male and female exposure groups throughout the study, but most consistently in the 9% chitosan group (approximately 40% to 60%). Increases in urine creatinine concentration tended to parallel the decreases in urine volume indicating proper kidney function.

Serum and hepatic vitamin concentrations were measured in Group B rats (Table 5 and Table C-1). Exposure concentration-dependent decreases were observed in serum vitamin A concentrations starting at week 13 in the male rats. The decreases reached statistical significance at weeks 13 (27%), 19 (26%), and 26 (29%) in 9% males and at weeks 13 (15%) and 26 (16%) in 3% males. Females were less affected with significant decreases observed in the 9% group at weeks 19 (18%) and 26 (21%). Exposure concentration-dependent decreases were also observed in serum vitamin E concentrations in male rats at all time points. The decreases were statistically significant at all time points in 3% (33% to 42%) and 9% males (79% to 82%) and in 1% males at week 13 (17%), with the 9% group measuring between 18% to 21% that of control values throughout the study. Females were less affected with significant decreases in serum vitamin E levels observed in the 9% group (approximately 60%) only (all time points). Hepatic vitamin E concentrations were significantly decreased at week 26 in 3% and 9% males (48% and 87%, respectively) and 9% females (80%). In the 9% group, levels of hepatic vitamin E measured only 13% and 20% of control values in the males and females, respectively. Serum concentrations of 1,25 (OH)_2_ vitamin D were significantly increased in 9% males (105% to 142%) and females (100% to 180%) at weeks 7, 19, and 26 compared to the control groups. Results of plasma hepatic vitamin K concentrations in Group C rats are not discussed or presented, as many samples were below the level of quantification.

Table 5 Serum and Hepatic Vitamin Concentration Data for Group B Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
Male
n
Week 7 | 9 | 10 | 10 | 10
Week 13 | 9 | 10 | 10 | 10
Week 19 | 9 | 10 | 10 | 10
Week 26 | 9 | 10 | 10 | 8
Serum vitamin A (µg/mL)
Week 7 | 0.532 ± 0.021 | 0.506 ± 0.033 | 0.513 ± 0.026 | 0.453 ± 0.018
Week 13 | 0.561 ± 0.024 | 0.499 ± 0.019 | 0.476 ± 0.022* | 0.410 ± 0.009**
Week 19 | 0.533 ± 0.028 | 0.506 ± 0.031 | 0.475 ± 0.019 | 0.392 ± 0.014**
Week 26 | 0.476 ± 0.019 | 0.444 ± 0.024 | 0.398 ± 0.017** | 0.336 ± 0.026**
Serum 1,25 (OH)_2_ vitamin D (pg/mL)
Week 7 | 124.4 ± 19.6 | 163.3 ± 21.7 | 183.2 ± 26.9 | 297.4 ± 41.0**
Week 13 | 70.1 ± 7.3 | 57.4 ± 5.3 | 77.3 ± 4.4 | 86.1 ± 8.5
Week 19 | 20.6 ± 2.8 | 21.7 ± 6.1 | 22.9 ± 2.2 | 42.3 ± 3.1**^b^
Week 26 | 27.7 ± 3.4^c^ | 28.0 ± 4.3 | 36.1 ± 4.6^b^ | 66.9 ± 11.9**
Serum vitamin E (µg/mL)
Week 7 | 19.33 ± 1.43 | 15.38 ± 1.29 | 12.92 ± 0.48** | 4.14 ± 0.23**
Week 13 | 21.08 ± 1.61 | 17.45 ± 1.06* | 12.27 ± 0.86** | 4.33 ± 0.27**
Week 19 | 20.59 ± 1.61 | 16.19 ± 0.96 | 12.86 ± 0.42** | 4.07 ± 0.32**
Week 26 | 19.66 ± 1.66 | 17.35 ± 1.37 | 12.35 ± 0.61** | 3.59 ± 0.65**
Liver vitamin E (µg/g)
Week 26 | 66.8 ± 16.2 | 55.0 ± 6.8 | 34.6 ± 2.2** | 8.5 ± 0.8**
Female
n
Week 7 | 10 | 10 | 10 | 10
Week 13 | 10 | 10 | 10 | 10
Week 19 | 10 | 10 | 10 | 10
Week 26 | 10 | 10 | 9 | 10
Serum vitamin A (µg/mL)
Week 7 | 0.272 ± 0.011 | 0.253 ± 0.007 | 0.260 ± 0.012 | 0.266 ± 0.012
Week 13 | 0.308 ± 0.020 | 0.295 ± 0.011 | 0.309 ± 0.019 | 0.281 ± 0.018
Week 19 | 0.283 ± 0.014 | 0.271 ± 0.015 | 0.291 ± 0.012 | 0.231 ± 0.010*
Week 26 | 0.316 ± 0.015 | 0.302 ± 0.014 | 0.294 ± 0.018 | 0.249 ± 0.010**
Serum 1,25 (OH)_2_ vitamin D (pg/mL)
Week 7 | 104.0 ± 15.1 | 96.7 ± 10.9 | 111.0 ± 8.7 | 208.1 ± 18.2**
Week 13 | 60.6 ± 7.5 | 60.7 ± 7.9 | 69.3 ± 11.0 | 110.1 ± 16.9
Week 19 | 11.6 ± 1.6 | 12.6 ± 1.7 | 15.8 ± 1.4 | 31.4 ± 3.2**
Week 26 | 19.2 ± 2.2 | 20.7 ± 4.2 | 28.6 ± 6.5 | 53.7 ± 5.8**
Serum vitamin E (µg/mL)
Week 7 | 18.65 ± 0.71 | 20.08 ± 0.87 | 18.38 ± 0.85 | 6.99 ± 0.58**
Week 13 | 19.81 ± 1.41 | 20.85 ± 1.06 | 20.19 ± 1.20 | 7.48 ± 0.38**
Week 19 | 21.02 ± 1.76 | 19.74 ± 1.75 | 19.86 ± 1.08 | 7.37 ± 0.57**
Week 26 | 20.94 ± 1.56 | 23.43 ± 1.66 | 22.23 ± 1.75 | 7.28 ± 0.64**
Liver vitamin E (µg/g)
Week 26 | 84.5 ± 8.9 | 97.1 ± 10.1 | 82.0 ± 11.8 | 17.2 ± 3.2**

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 7.

Digestive parameters were calculated for Group C rats and are listed in Table 6. Compared to the control groups, percent fat digested was significantly decreased at week 6 in 9% males (28%) and females (14%), during week 12 in 3% and 9% males (8% and 33%, respectively), during week 18 in 9% males (20%) and females (10%), and during week 24 in all exposed groups of males and females (up to 32%). Calcium absorption was significantly increased in 9% females during weeks 12 (55%) and 24 (154%). Fecal weight was significantly increased in 3% and 9% males (up to 170%) and females (up to 126%) during each collection period and in 1% females during weeks 12, 18, and 24 (18% to 29%). Fecal moisture was significantly increased in 9% males and females at all time points (10% to 15%), in 3% males (4%) at week 6, and in 3% females (7%) at weeks 12 and 18.

Table 6 Digestive Data for Group C Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
Male
n
Weeks 6–7 | 10 | 10 | 10 | 10
Weeks 12–13 | 10 | 10 | 10 | 10
Weeks 18–19 | 10 | 10 | 10 | 9
Weeks 24–25 | 10 | 10 | 10 | 10
Fat digested (%)
Weeks 6–7 | 97.04 ± 0.40 | 97.55 ± 0.22 | 94.37 ± 0.84 | 69.55 ± 3.01**
Weeks 12–13 | 94.79 ± 0.46 | 93.36 ± 0.83 | 87.08 ± 0.68** | 63.50 ± 2.40**
Weeks 18–19 | 97.56 ± 0.58 | 98.48 ± 0.19 | 95.87 ± 0.70 | 77.59 ± 1.83**
Weeks 24–25 | 97.01 ± 0.19 | 95.61 ± 0.32** | 92.14 ± 0.87** | 66.18 ± 3.24**
Calcium absorbed (%)
Weeks 6–7 | 31.69 ± 1.84 | 34.57 ± 4.05 | 27.54 ± 1.83 | 33.01 ± 1.59
Weeks 12–13 | 19.81 ± 3.36 | 14.73 ± 0.76 | 18.42 ± 3.25 | 28.01 ± 2.69
Weeks 18–19 | 13.33 ± 4.33 | 18.42 ± 5.43 | 3.64 ± 2.62 | 11.11 ± 1.35
Weeks 24–25 | 2.93 ± 1.54 | 5.14 ± 1.08 | 0.70 ± 1.57 | 9.46 ± 1.88
Fecal weight (g)
Weeks 6–7 | 21.42 ± 0.68 | 21.01 ± 1.93 | 31.33 ± 0.90** | 52.39 ± 2.85**
Weeks 12–13 | 24.32 ± 1.68 | 27.70 ± 1.37 | 32.84 ± 1.73** | 47.59 ± 4.30**
Weeks 18–19 | 23.11 ± 1.25 | 22.67 ± 1.85 | 33.30 ± 1.72** | 62.38 ± 3.67**^b^
Weeks 24–25 | 26.43 ± 1.12 | 25.75 ± 0.73 | 37.17 ± 1.11** | 56.35 ± 3.45**
Fecal moisture (%)
Weeks 6–7 | 45.0 ± 0.5 | 42.0 ± 1.6 | 46.8 ± 0.4* | 51.0 ± 0.8**
Weeks 12–13 | 46.8 ± 2.0 | 49.0 ± 0.8 | 48.8 ± 0.6 | 53.6 ± 0.8**
Weeks 18–19 | 47.7 ± 1.1 | 45.3 ± 1.8 | 49.1 ± 0.7 | 54.8 ± 1.5**^b^
Weeks 24–25 | 47.2 ± 0.6 | 45.7 ± 0.5 | 49.3 ± 0.7 | 53.1 ± 0.8**
Female
n
Weeks 6–7 | 10 | 10 | 10 | 9
Weeks 12–13 | 10 | 10 | 10 | 10
Weeks 18–19 | 10 | 10 | 10 | 10
Weeks 24–25 | 8 | 9 | 10 | 10
Fat digested (%)
Weeks 6–7 | 96.47 ± 0.49 | 95.53 ± 1.30 | 95.46 ± 0.66 | 83.23 ± 2.69**
Weeks 12–13 | 97.12 ± 1.58 | 98.54 ± 0.99 | 97.27 ± 1.16 | 91.95 ± 2.70
Weeks 18–19 | 99.17 ± 0.18 | 97.52 ± 0.50 | 97.15 ± 1.24 | 89.61 ± 2.53**
Weeks 24–25 | 98.66 ± 0.08 | 97.68 ± 0.39** | 96.79 ± 0.49** | 86.73 ± 1.55**
Calcium absorbed (%)
Weeks 6–7 | 31.44 ± 2.35 | 24.42 ± 2.54 | 24.36 ± 2.50 | 32.29 ± 1.69
Weeks 12–13 | 14.84 ± 1.76 | 17.03 ± 3.11 | 17.96 ± 1.22 | 23.02 ± 2.39*
Weeks 18–19 | 8.96 ± 3.00 | 9.78 ± 1.98 | 0.47 ± 3.37 | 13.07 ± 1.65
Weeks 24–25 | 5.65 ± 2.84 | 9.23 ± 2.74 | 8.25 ± 1.59 | 14.50 ± 1.40*
Fecal weight (g)
Weeks 6–7 | 14.37 ± 0.91 | 15.76 ± 0.60 | 19.85 ± 1.64** | 32.61 ± 1.67**^b^
Weeks 12–13 | 15.37 ± 0.60 | 18.41 ± 1.28* | 21.11 ± 1.07** | 30.83 ± 2.78**
Weeks 18–19 | 16.30 ± 0.86 | 19.23 ± 0.97* | 25.21 ± 1.42** | 36.58 ± 2.41**
Weeks 24–25 | 16.01 ± 0.92^b^ | 20.66 ± 1.14** | 24.85 ± 1.19** | 35.78 ± 2.27**
Fecal moisture (%)
Weeks 6–7 | 45.3 ± 1.1 | 45.3 ± 0.4 | 47.3 ± 0.8 | 50.0 ± 0.9**^b^
Weeks 12–13 | 45.9 ± 0.7 | 47.5 ± 1.0 | 49.3 ± 0.5** | 52.7 ± 1.0**
Weeks 18–19 | 46.1 ± 1.1 | 47.2 ± 0.4 | 49.5 ± 0.9** | 53.0 ± 0.7**
Weeks 24–25 | 47.2 ± 0.6^b^ | 48.4 ± 1.4 | 49.2 ± 0.6 | 52.6 ± 0.9**

* Significantly different (P ≤ 0.05) from the control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 10.

Male rats did not display any changes in testis or epididymis weights or sperm parameters, indicating that chitosan did not exhibit the potential to be a reproductive toxicant in male rats (Table E-1).

Bone parameters in Groups A and B rats were generally unaffected by chitosan exposure (Table C-2). Bone moisture was significantly increased, relative to the control group, in 9% females (7%).

The absolute and relative liver weights of Group A 9% males and females were significantly less (22% and 21% lower, respectively) than those of the respective control groups (Table 7 and Table D-1). The absolute and relative thymus weights of Group A 3% and 9% males and 9% females were significantly less than those of the controls (Table D-1).

Table 7 Liver Parameter Data for Group A Rats in the Six-month Feed Study of Chitosan

| 0% | 1% | 3% | 9%
Male
n ^a^ | 10 | 10 | 10 | 10
Necropsy body wt | 669 ± 20 | 702 ± 21 | 687 ± 23 | 612 ± 17
Liver weight^b^
Absolute | 25.19 ± 0.87 | 24.87 ± 1.35 | 23.74 ± 1.51 | 19.53 ± 0.71^##^
Relative | 37.662 ± 0.731 | 35.321 ± 1.179 | 34.345 ± 1.411^#^ | 31.933 ± 0.817^##^
Periportal, Fatty Change^c^ | 6 (1.7)^d^ | 3 (1.7) | 6 (1.3) | 3 (1.0)
Female
n | 10 | 10 | 10 | 10
Necropsy body wt | 338 ± 11 | 335 ± 13 | 328 ± 11 | 301 ± 13
Liver weight
Absolute | 12.54 ± 0.82 | 12.47 ± 0.39 | 11.85 ± 0.29 | 9.85 ± 0.20^##^
Relative | 36.900 ± 1.502 | 37.341 ± 0.444 | 36.346 ± 0.904 | 33.036 ± 0.910^#^
Periportal, Fatty Change | 7 (1.1) | 4 (1.0) | 4 (1.0) | 0**

^#^ Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

^##^ Significantly different (P ≤ 0.01) from the control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the control group by the Fisher exact test.

^a^ Number of animals with liver weighed and with liver examined microscopically.

^b^ Liver weights (absolute weights) and body weights are given in grams; Liver-weight-to-body-weight ratios (relative weights) are given as mg liver weight/g body weight (mean ± standard error).

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

There was a significant decrease in the incidence of periportal fatty change of the liver in Group A female rats in the 9% group compared to the control group and decreases in 1% and 3% females that resulted in a negative trend (Table 7 and Table A-2). In male rats, there were decreases in the incidences of periportal fatty change in the 1% and 9% groups, and the severities were decreased in the 3% and 9% groups (Table 7 and Table A-1). Fatty change was characterized by hepatocytes with clear vacuoles (lipid), mostly located within the periportal region of the liver (zone 1) (Figure 3).

Figure 3

Section of the Liver from a Control Male Sprague Dawley Rat from the Six-month Feed Study of Chitosan with a Moderate Degree of Fatty Change (H&E)

There is a predominant periportal distribution of affected hepatocytes.

Hepatocytes contained large, well-defined, single round vacuoles (macrovesicular) within each cell that displaced the nuclei and cytoplasm to the cell periphery (Figure 4) and can be compared with a liver lacking fatty change (Figure 5).

Figure 4

Higher Magnification of Figure 3 (H&E)

The fatty change is characterized by round, discrete vacuoles within hepatocytes that displace the nuclei and cytoplasm to the periphery.

Figure 5

Section of the Liver with a Lack of Fatty Change from a Male Sprague Dawley Rat Exposed to 9% Chitosan in Feed for Six Months (H&E)

There is some minimal vacuolization within many hepatocytes. The vacuoles lack distinct round borders and the nuclei are centrally located, consistent with glycogen accumulation.