# Materials and Methods

## Procurement and Characterization of Chitosan

Chitosan was obtained from Vanson HaloSource, Inc. (Redmond, WA), in one lot (02-ASSF-0715), which was used in the 6-month study. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (MRI) (Kansas City, MO) and by the study laboratory at Battelle Columbus Operations (Columbus, OH) (Appendix F). Reports on analyses performed in support of the chitosan studies are on file at the National Institute of Environmental Health Sciences.

The test article, an off-white powder, was identified using infrared and proton nuclear magnetic resonance (NMR) spectroscopy. The percentage of deacetylation of the test article, determined by proton NMR, ranged from 85.97% to 87.17%, with an average of 86.5%. All spectra were consistent with the literature spectra,^38,39^ and with the Sadtler spectral database.

The moisture content for lot 02-ASSF-0715 was determined using weight loss on drying, the inorganic content was determined on the dried test article by ashing, viscosity was determined using a Brookfield viscometer, and the most abundant molecular weight was determined using gel permeation chromatography (GPC) with refractive index (RI) detection.

Moisture content was 4.50% water, the average inorganic content was 2.13%, and viscosity was 81.3 centipoise. GPC/RI indicated one major peak and the determined molecular weight of the bulk chemical ranged from 62,755 to 87,343 daltons (Da). This resulted in an average molecular weight of 81,644 g/mol, or approximately 82 kDa, classifying the test article as a low molecular weight chitosan (LMWCS). A sample of lot 02-ASSF-0715 was submitted to Covance Laboratories, Inc. (Madison, WI), for nutritional and contaminant testing using standard methods. Levels of organochlorine and organophosphorous pesticides, nitrosamines, and aflatoxins were below the detection limits of the analytical methods. The purity of lot 02-ASSF-0715 was estimated to be approximately 94% based on the analysis of moisture and inorganic content. Taken together, these data indicated that the test article was chitosan.

To ensure stability, the test article was stored in sealed amber glass vials at room temperature. Reanalysis of the test article was performed during the study using GPC/RI and no degradation of the test article was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared approximately monthly by mixing chitosan with feed. Dose formulations were stored in lined plastic buckets sealed with lids and stored at −30°C to −15°C for up to 42 days.

Homogeneity studies of approximately 0.5% and 9% formulations (5,046 and 90,049 µg/g, respectively) and stability studies of an approximately 0.5% (5,046 µg/g) formulation were performed by the analytical chemistry laboratory using GPC/RI. Two peaks were attributed to chitosan with retention times of approximately 6.9 minutes and 12.1 minutes, respectively. Chitosan quantitation was based on the larger polymeric components of the first peak only because vehicle components co-eluted with the later oligomeric peak. Homogeneity studies of 1% and 9% (10 and 90 mg/g in feed, respectively) dose formulations were performed by the study laboratory using GPC/RI. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in lined plastic buckets sealed with lids at temperatures up to room temperature and for at least 7 days under simulated animal room conditions.

Periodic analyses of the dose formulations of chitosan were performed by the study laboratory using GPC/RI. Of the dose formulations analyzed, all nine were within 10% of the target concentrations (Table F-3). Animal room samples were also analyzed; all three were within 10% of the target concentrations.

## Animal Source

Male and female Sprague Dawley [Crl:CD(SD)] rats were obtained from Charles River Laboratories (Portage, MI) for use in the 6-month study.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Six-month Study

The rats were 5 to 6 weeks old upon receipt. Rats were quarantined for 12 to 15 days and were 7 to 9 weeks old on the first day of the study. Before the study began, five male and five female rats were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix I). A positive test result for parvovirus occurred in one animal at the 4-week timepoint. Additional testing of serum from this animal and other sentinel animals via other testing methodologies deemed the original positive result to be a false positive. All other test results were negative for rodent pathogens.

The animals in this study were split into three groups, the core group, Group A, and two special study groups, Groups B (vitamin and bone analysis) and C (fat digestion, hematology, clinical chemistry, and urinalysis). Different parameters were evaluated in each group, which allowed for the collection of extensive endpoints (Table 1). Groups of 10 male and 10 female rats were examined per endpoint and there was no crossover of analyses between any of the groups. Group A rats were fed diets containing 0%, 1%, 3%, or 9% chitosan for 25 weeks. Groups B and C rats were fed diets containing the same concentrations for up to 26 weeks. Feed and water were available ad libitum. The AIN-93M diet was used for this study instead of the NTP-2000 diet because of the high levels of fat-soluble vitamins and higher total fat content found in the NTP-2000 diet. The NTP-2000 feed contains almost double the amount of required fat-soluble vitamins and has a higher fat content (7% to 8%) than the AIN-93M feed (4%).^40-42^ One of the primary rationales for this chitosan study was the potential for decreases in fat-soluble vitamin concentrations, and therefore, utilizing a diet with lower levels of preexisting vitamins and a lower fat content was ideal to avoid confounding potential results. Rats were housed individually. Feed consumption was recorded weekly for core study rats. Core study rats were weighed and clinical findings were recorded initially, on day 8, weekly thereafter, and at the end of the study. Details of the study design and animal maintenance are summarized in Table 2.

Table 1 Distribution of Evaluated Parameters

| Group
Parameter | A | B | C
Feed consumption | X | – | –
Body weights | X | – | –
Clinical findings | X | – | –
SMVCE | X | – | –
Bone histomorphometry | X | – | –
Gross lesions and histopathology | X | – | –
Vitamin A (serum and liver) | – | X | –
Vitamin E (serum and liver) | – | X | –
1,25 (OH)_2_ Vitamin D (serum) | – | X | –
Bone calcium, ash, and moisture | – | X | –
Hematology | – | – | X
Clinical chemistry | – | – | X
Vitamin K_1_ (plasma and liver) | – | – | X
Feed and fecal analysis | – | – | X
Urinalysis | – | – | X

Table 2 Experimental Design and Materials and Methods in the Six-month Feed Study of Chitosan

Six-month Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
Charles River Sprague Dawley [Crl:CD(SD)] rats
Animal Source
Charles River Laboratories (Portage, MI)
Time Held Before Study
Group A (core study): 14 (males) or 15 (females) days Groups B and C (special studies): 12 (males) or 13 (females) days
Average Age When Study Began
7 to 8 weeks (Group A males and Groups B and C males and females) 8 to 9 weeks (Group A females)
Date of First Exposure
Group A: August 31 (males) or September 1 (females), 2006 Groups B and C: August 29 (males) or 30 (females), 2006
Duration of Exposure
Group A: 25 weeks Groups B and C: 26 weeks
Date of Last Exposure
Group A: February 15 (males) or 16 (females), 2007 Groups B and C: February 20 (males) or 21 (females), 2007
Necropsy Dates
Group A: February 15 (males) or 16 (females), 2007 Groups B and C: February 20 (males) or 21 (females), 2007
Average Age at Necropsy
32 to 33 weeks (Group A females and Groups B and C males and females) 31 to 32 weeks (Group A males)
Size of Study Groups
10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo
Diet
AIN-93M maintenance purified meal diet (Purina TestDiet, Richmond, IN), available ad libitum, changed twice weekly
Water
Tap water (Columbus, OH municipal supply) via automatic watering system (Edstrom Industries, Inc. Waterford, WI), available ad libitum
Cages
Polycarbonate solid-bottom (Lab Products, Inc., Seaford, DE), changed weekly, rotated in rack every 2 weeks
Bedding
Irradiated hardwood bedding chips (P.J. Murphy Forest Products Corporation, Montville, NJ), changed weekly
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc), changed and rotated every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: 10/hour
Exposure Concentrations
0%, 1%, 3%, and 9% in feed, available ad libitum
Type and Frequency of Observation
Observed twice daily; Group A rats were weighed and clinical findings were recorded initially, on day 8, weekly thereafter, and at the end of the study. Feed consumption was recorded weekly for Group A rats and during fecal collection periods for Group C rats.
Method of Euthanasia
100% Carbon dioxide
Necropsy
Necropsies were performed on all Group A rats at the end of the study (week 25). Organs weighed were heart, right kidney, liver, lung, right ovary, parathyroid gland, right testis, thymus, thyroid gland and parathyroid gland together, and uterus. Lengths of both tibias and the left femur were measured.
Clinical Pathology
Blood was collected via the retroorbital plexus from all Group C rats on the first day of weeks 7, 13, 19, and 25 for hematology (week 25 only) and clinical chemistry. Urine was collected from Group C rats for 24 hours beginning the last day of weeks 6, 12, 18, and 24. Hematology: hematocrit (auto and manual); hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, calcium, phosphorous, total protein, albumin, cholesterol, triglycerides, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, bile acids, total osteocalcin, and parathyroid hormone Urinalysis: creatinine, volume, and deoxypyridinoline
Histopathology
Histopathology was performed on 0% and 9% Group A rats. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone (left femur and tibia) with marrow, brain, clitoral gland, esophagus, eye, Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung (with mainstem bronchus), lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus. The kidney and liver of males and females and the parathyroid gland and prostate gland of males were also examined in the 1% and 3% groups.
Sperm Motility
At the end of the study, sperm samples were collected from male Group A rats for sperm count and motility evaluations. The following parameters were evaluated: spermatid heads per gram testis and per testis, spermatid heads per gram cauda and per cauda, and epididymal spermatozoal motility. The left cauda, left epididymis, and left testis were weighed.
Digestion Studies
Feces were collected from Group C rats for 8 days beginning weeks 6, 12, 18, and 24 and analyzed for calcium, fat, and moisture. Fecal calcium and fat content were compared to that in feed samples collected during the same time period to produce values for fat digested and calcium absorbed.
Serum and Hepatic Vitamins
Blood was collected from the retroorbital plexus of Groups B and C rats on the first day of weeks 7, 13, 19, and 25 (Group C), and 26 (Group B). At study termination (week 26), liver samples were collected from Groups B and C rats. Blood and liver samples were analyzed for vitamins A, E, 1,25 (OH)_2_ D, and/or K_1_.
Bone Analysis
At study termination (week 26), right and left femurs were collected from Group B rats, and calcium, ash, and moisture levels were measured.

On the first day of weeks 7, 13, 19, and 26, blood was collected from all Group B rats via the retroorbital plexus under CO_2_/O_2_ anesthesia for determination of vitamins A, E, and 1,25 (OH)_2_ vitamin D concentrations. Blood was collected into tubes, allowed to clot, and centrifuged. Sera were stored at approximately −70°C until analysis. Blood samples for vitamin K_1_ concentrations in Group C rats, collected into tubes containing EDTA at the same time as hematology collections, were centrifuged; the plasma was harvested, snap frozen, and stored at −70°C protected from light. At study termination (week 26), liver samples were collected from surviving Group B and C rats, processed, and stored frozen for determination of vitamins A and E (Group B) or vitamin K_1_ (Group C) concentrations. Blood and liver samples were analyzed by high performance liquid chromatography for vitamins A and E (Covance Laboratories, Inc.), by competitive enzyme immunoassay for 1,25 (OH)_2_ vitamin D (Antech Diagnostics, Morrisville, NC), or by gas chromatography/mass spectrometry for vitamin K_1_ (Analytics, Inc., Gaithersburg, MD). Because most values for vitamin K_1_ were below the limit of quantitation, the results are not presented in this Toxicity Study Report.

For 8 days beginning during weeks 6, 12, 18, and 24, Group C rats were placed in metabolism cages (Nalgene Company, Rochester, NY) for fecal and urine collection. During collection periods, rats were allowed control or dosed feed and water ad libitum, and feed samples were collected. Feces were collected for a period of 8 days, with each day’s collection being combined with previous days’ collection and stored at approximately −20°C. Feces were stored at −70°C after each collection period until shipping to Covance Laboratories, Inc., on dry ice for analyses of calcium, fat, and moisture; the feed samples were also sent for analysis. Fat content in feed and feces was determined gravimetrically by Soxhlet extraction. Feed consumption, fat intake [(total feed consumed per interval) × (% fat in feed/100)], and fat excretion [fecal weight × (% fecal fat/100)], were calculated to estimate fat digestion: {[(fat intake − fat excreted in feces)/fat intake] × 100}. Calcium concentrations in feed and feces were determined using inductively coupled plasma emission spectrometry. Moisture was determined by weight loss upon drying. Urine was collected on ice for each Group C rat over a 24-hour period during the last day in the metabolism cage and coincided with the last day of fecal collection. Total urine collected was transferred to centrifuge tubes and the volume was recorded. Urine creatinine was measured using a Hitachi 911^TM^ chemistry analyzer (Roche Diagnostics, Indianapolis, IN), and deoxypyridinoline was measured using a Metra Total DPD Enzyme Immunoassay Kit (Quidel, San Diego, CA).

On the last day in the metabolism cage, at the beginning of weeks 7, 13, 19, and 25, blood was collected from all Group C rats via the retroorbital plexus under CO_2_/O_2_ anesthesia for hematology (week 25 only) and clinical chemistry. Blood samples for hematology were collected in tubes containing EDTA as an anticoagulant. Hematology parameters were determined using an Advia 120 hematology analyzer (Bayer Diagnostics Division, Tarrytown, NY). Blood for clinical chemistry determinations was collected in tubes without anticoagulant, allowed to clot, and centrifuged and then the serum was harvested. Except as noted, clinical chemistry parameters were determined using a Hitachi 911^TM^ chemistry analyzer (Roche Diagnostics). For osteocalcin and parathyroid hormone, serum was stored frozen at −20°C until analysis. Serum osteocalcin was measured using a Rat-MID^TM^ Osteocalcin ELISA (Nordic Bioscience Diagnostics, Herlev, Denmark). Serum parathyroid hormone was measured using an Intact PTH Enzyme Immunoassay Kit (ALPCO Diagnostics, Salem, NH).

At study termination (week 26), right and left femurs were collected from the Group B rats for determination of calcium, ash, and moisture. Covance Laboratories, Inc., determined bone moisture by measuring weight loss upon drying, calcium by inductively coupled plasma emission spectrometry, and ash gravimetrically.

At the end of the study (week 25), samples were collected for sperm motility and vaginal cytology evaluations on Group A rats. The parameters evaluated are listed in Table 2. Due to inconsistent sample collection and slide staining, an assessment of estrous cyclicity could not be made. Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all Group A animals at study termination (week 25). The heart, right kidney, liver, lung, right ovary, parathyroid gland, right testis, thymus, thyroid gland and parathyroid gland together, and uterus were weighed. Both tibias and both femurs were collected; the lengths of both tibias and the left femur were measured. The right tibia and femur were dehydrated in ethanol (70% to 100%) and infiltrated with glycol methacrylate. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on 0% and 9% rats. The kidney and liver of males and females and the parathyroid gland and prostate gland of males were examined in all exposure groups. Table 2 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to an NTP Pathology Peer Review (PPR) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PPR coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^43^ and Boorman et al.^44^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^45^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnet^46^ and Williams.^47,48^ Hematology, clinical chemistry, urinalysis, serum and liver vitamin concentrations, digestive and bone parameters, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^49^ (as modified by Williams^50^) and Dunn.^51^ Jonckheere’s test^52^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^53^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

The 6-month study was conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^54^ In addition, as records from the 6-month study were submitted to the NTP Archives, this study was audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.