# Introduction

Figure 1

Chitosan (CASRN 9012-76-4; Chemical Formula: [C_6_H_11_NO_4_]_n_)

Synonyms: 2-Amino-2-deoxy-beta-D-glucosamine; deacetylated chitin; poliglusam; poly. (D-glucosamine).

Trade names: Celox, Chicol, Chitopearl, CTFA 04299, Flonac N, Kytex H, Sea Cure F.

## Chemical and Physical Properties

Chitosan is a cationic carbohydrate polymer that is commercially derived from the deacetylation of chitin. The primary unit of the chitosan polymer is D-glucosamine. Chitosan exists in multiple forms that can differ in molecular weight [3 to 3,600 kilodaltons (kDa)] and in the degree of deacetylation (40% to 100%).^1^ Chitosan is defined as chitin that is sufficiently deacetylated to form soluble amine salts. Solubility in aqueous, acidic media occurs when deacetylation of chitin reaches approximately 50%.^2^ In addition to the degree of deacetylation, chitosan solubility is also dependent on the molecular weight and the distribution of the remaining acetyl groups on the polymer.^3^ Chitosan is insoluble in alkaline solutions at pH levels above 6.5. Chitosan products are highly viscous, resembling natural gums.^4^

## Production, Use, and Human Exposure

Chitin, from which chitosan is derived, is a naturally occurring carbohydrate polymer second only to cellulose in abundance. Chitin is a structural component found in the exoskeleton of arthropods and in the cell walls of fungi and yeast.^2^ The primary unit of chitin, N-acetyl-D-glucosamine, forms the polymeric structure via 1 → 4 glycosidic bonds. Discarded crab and shrimp shells from the seafood industry are the primary source material of chitin for the commercial production of chitosan.^5^ For chitosan production, seafood shells are deproteinized by treatment with an aqueous 3% to 5% sodium hydroxide (NaOH) solution. The resulting product is neutralized and calcium is removed by treatment with an aqueous 3% to 5% hydrochloric acid (HCl) solution at room temperature resulting in a white or slightly pink precipitate of chitin. The N-deacetylation of chitin is done by treatment with an aqueous 40% to 45% NaOH solution, and the precipitate is washed with water. The precipitate is then dissolved in aqueous 2% acetic acid and the insoluble material is removed. The resulting clear supernatant solution is neutralized with aqueous NaOH solution producing chitosan as a white precipitate.

Chitosan is used in a wide range of products including use as a flocculating agent for water and waste treatment and as a chelating agent for removal of traces of heavy metals from aqueous solutions.^4^ In agriculture, chitosan is used as a plant growth regulator through foliar application and as an antimicrobial agent and a time-release reservoir for fertilizers in soil amendments.

Chitosan has several current or proposed biomedical applications. Chitosan is considered to be hemostatic due to its cationic nature. As such, wound dressings manufactured from chitosan are available for clinical use.^6^ Several drug delivery systems based on chitosan nanoparticles are currently being investigated. Chitosan nanoparticles are capable of permeating the blood brain barrier, and the mucoadhesive properties of chitosan have been shown to enhance drug absorption.^2,7^ Chitosan has also been evaluated for the manufacture of ocular bandage lenses and biodegradable surgical and dental implants.^8^

In cosmetics, chitosan is used in a variety of hair and skin products, including hair and body washes, coloring shampoos, and agents for skin cleaning and protection.^9^ Chitosan has also been evaluated for use as an additive to toothpaste for prevention of enamel erosion.^10^

As a dietary supplement, chitosan is marketed and sold in weight-loss products, but the mechanism behind chitosan-induced inhibition of fat digestion is not well understood. It has been proposed that chitosan acts as a weak anion exchanger and decreases intestinal cholesterol absorption while also increasing the excretion of bile acids.^11-13^ Another possible mechanism is that chitosan traps fat in the intestines by increasing the viscosity of the intestinal contents and preventing the hydrolysis of triglycerides.^13-15^ The manufacturer-recommended consumption of chitosan as a weight-loss product in humans typically averages 1,000 mg per day, or approximately 14.3 mg/kg per day (based on a 70 kg adult).^16,17^ There are no available dose or prevalence data for human consumption of chitosan as a dietary supplement.

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

The systemic absorption and distribution of chitosan following oral exposure are likely influenced by the molecular weight of the polymer. The effect of molecular weight on chitosan absorption has been evaluated in male Sprague Dawley rats. Oral gavage administration of chitosan with molecular weights of 3.8, 7.5, 13, 22, or 230 kDa resulted in maximum plasma chitosan concentrations (C_max_) of 20.23, 9.30, 5.86, 4.32, or less than 0.5 μg/mL, respectively.^18^ The results of this study suggest that the absorption of chitosan from the gastrointestinal tract following oral exposure is inversely related to chitosan molecular weight, as there is likely low bioavalability associated with the higher molecular weight chitosan polymers.

The biodegradation of chitosan influences absorption and distribution because both are dependent on molecular weight. The biodegradation of chitosan in vivo is dependent on the degree of deacetylation.^19^ Enzymatic degradation of chitosan depends on the ability to hydrolyze glucosamine-glucosamine, glucosamine-N-acetyl-glucosamine and N-acetyl-glucosamine-N-acetyl-glucosamine linkages.^1^ Degradation of chitosan in vertebrates is thought to occur predominantly by lysozymes and bacterial enzymes in the colon.^1^ While eight human chitinases have been identified with three showing enzymatic activity, their capacity to degrade chitosan has not been investigated.^1-20^

## Toxicity

### Experimental Animals

The acute toxicities of chitosan and chitosan oligomers prepared by enzymatic depolymerization of chitosan have been evaluated. Hirano^5^ reported the oral LD_50_ for chitosan as 16 g/kg body weight in mice. No clinical signs of toxicity were observed following a single oral administration of chitosan oligomers up to 10 g/kg in male and female Kunming strain mice.^21^

No significant differences in weight gain were observed between exposed male Charles River albino rats and the controls in a 4-week study with 1% or 5% dietary chitosan.^22^ In male Wistar rats, no significant differences in growth, feed intake, liver weight, or dried fecal weight were observed between control and chitosan-fed (2% or 5%) animals after 21 days.^23^ In male Sprague Dawley rats fed chitosan in the diet for 8 weeks, no toxicity was observed in animals at concentrations up to 5%, progressive growth reductions and clinical pathology disturbances occurred at 10% and 15%, and enlargement of the liver and kidneys was observed at 15%.^24^

In female BALB/c mice fed a 5% (4.4 ± 0.7 g/day per animal) chitosan diet for 4 weeks, body weight reduction correlated with significantly decreased feed consumption and alterations in normal gut flora.^25^

In a study to evaluate mineral and fat-soluble vitamin status in male Charles River Japan Sprague Dawley rats, exposure to a diet containing 5% chitosan for 2 weeks caused a decrease in mineral absorption and bone mineral content.^26^ Decreased serum vitamin E was observed in rats fed 5% chitosan with ascorbic acid supplementation in the diet. Serum vitamin E depletion was not observed in rats given glucosamine instead of chitosan.

Depletion of fat-soluble vitamins has been associated with a variety of neurologic and metabolic disorders. Male C57BL/6 mice fed a vitamin E-deficient diet showed signs of cognitive decline after 3 months of exposure and had increased lipid peroxidation products in brain tissue after 6 months of exposure.^27^ Male rats fed a vitamin A-deficient diet for 3 months had lower levels of serum cholesterol, HDL-cholesterol, and triacylglycerol, as well as decreased synthesis of liver fatty acids.^28^

The toxicity of glucosamine oligomers has been evaluated in male and female Charles River Japan F344 rats fed 0%, 0.04%, 0.2%, or 1% oligoglucosamine in the diet for 90 days.^29^ Glucosamine oligomers are prepared by hydrolysis of chitosan and, similar to the chitosan utilized in this 6-month study, are considered low molecular weight chitosan. In the 1% (653.1 mg/kg per day in males, 719.8 mg/kg per day in females) group, erythema and edema in the snout and on the forelimbs and loss of fur on the forelimbs were observed in both male and female rats. Neutrophilic infiltration in the nasal cavity was also observed in both sexes in the 1% group. These findings were considered to be caused by topical exposure to glucosamine oligomers during feeding and grooming. Decreased feed consumption and body weight gain were also observed in animals in the 1% group in this study and were thought to be the result of feeding difficulty due to the snout and forelimb lesions described above. Rats receiving 1% oligoglucosamine also displayed lower weights of the uterus, ovary, seminal vesicles, and testes (with fewer germ cells).

The intravenous administration of chitosan has been investigated due to the development of chitosan formulations for drug delivery. No adverse effects were reported in rabbits up to 60 days following intravenous administration of chitosan oligosaccharides (prepared by oxidative depolymerization of chitosan) at doses up to 8.6 mg/kg daily for 5 consecutive days.^30^ In this study, increased lysozyme activity was observed in rabbit serum collected the day after the last intravenous injection. Chemical modifications and nanoparticle suspensions of chitosan are currently being investigated for drug delivery.^1^ As such, modifications made to chitosan could alter the toxicity of the unmodified chitosan polymer.

No adverse effects of chitosan were reported in eye or skin irritation tests in rabbits or guinea pigs, respectively.^31^

### Humans

Studies designed to evaluate the effectiveness of chitosan as a weight-loss supplement suggest that chitosan is well tolerated in humans. No adverse effects were reported in male (4.5 g chitosan per day) or female (2.5 g per day) volunteers following oral chitosan administration for 12 days.^32,33^ Additionally, no adverse effects were reported following oral administration of chitosan at up to 6.75 g per day for 8 weeks in male and female volunteers.^34^

## Carcinogenicity

No 2-year carcinogenicity studies of chitosan were identified in the available literature.

Carcinogenicity and chronic toxicity have been evaluated for N-acetyl-D-glucosamine, a monomeric constituent of chitosan. F344 rats administered N-acetyl-D-glucosamine at concentrations up to 5% in the diet (1,935 mg/kg per day in males and 2,244 mg/kg per day in females) for 104 weeks had no associated increases in tumor response.^35^ In a second study in F344 rats, administration of N-acetyl-D-glucosamine in feed at concentrations up to 5% in the diet (2,323 mg/kg per day in males and 2,545 mg/kg per day in females) for 52 weeks did not induce an increase in tumor response.^35^

## Developmental and Reproductive Toxicity

A limited number of developmental and reproductive toxicity studies were identified in the literature.

In a multigenerational prenatal and postnatal assessment of high molecular weight chitosan (HMWCS), F_0_ time-mated ICR mice were administered 0, 125, 500, or 2,000 mg/kg HMWCS via a single intraperitoneal injection on gestational day 6 (GD 6) and subjected to a laparotomy or allowed to litter.^36^ F_1_ offspring (1 mouse/sex per litter) from the same exposure group were mated and females similarly subjected to either a laparotomy or allowed to litter to produce an F_2_ generation. F_0_ dams in the 2,000 mg/kg group exhibited signs of maternal toxicity (mortality and diarrhea). F_0_ dams in the 500 and 2,000 mg/kg groups displayed dose-dependent increases in vaginal bleeding, postimplantation loss, and lower spleen weights. Fetal weights for both generations were lower in the 2,000 mg/kg group. There were no external, visceral, or skeletal malformations attributed to chitosan administration. F_0_ dams allowed to litter displayed a dose-related reduction in litter size. F_1_ mice exposed in utero to 2,000 mg/kg HMWCS and examined on postnatal day 21 (PND 21) exhibited higher uterus, ovary, and thymus weights. Female F_1_ mice exposed in utero to 2,000 mg/kg HMWCS displayed lower thymus weights on PND 56. F_2_ mice exposed in utero to 2,000 mg/kg HMWCS displayed lower testis and ovary weights on PNDs 21 and 56.

Chitosan oligomers did not induce morphologic sperm abnormalities in male mice following oral gavage daily for 5 days with up to 5,000 mg/kg.^21^

The effects of chitosan nanoparticles (spherical; 200 ± 6 nm or 340 ± 10 nm diameter) have been examined in zebrafish (Danio rerio) embryos. Embryos exposed 4 to 5 hours after fertilization to 0, 5, 10, 20, 30, or 40 μg/mL (200 nm particles) or 0, 10, 20, or 40 μg/mL (340 nm particles) displayed concentration-dependent decreases in hatching rates and increases in mortality 96 hours after exposure.^37^ Increased rates of cell death and reactive oxygen species production were observed in all exposure groups. Exposure to 200 nm, but not 340 nm, chitosan nanoparticles induced developmental malformations in embryos, including bent spines, pericardial edema, and opaque yolks.

## Genetic Toxicity

No in vitro or in vivo studies evaluating chitosan for mutagenic effects were identified in the available literature.

Chitosan oligomers were negative at concentrations up to 5,000 μg/plate in Salmonella typhimurium strains TA97, TA98, TA100, and TA102 with and without rat liver S9 metabolic activation enzymes, and they were negative for micronucleus induction in mouse bone marrow following oral gavage for 2 days at up to 5,000 mg/kg.^21^

## Study Rationale

Chitosan was nominated for study by the National Cancer Institute due to widespread human exposure, especially through use as a dietary supplement for body weight reduction, and for concerns regarding potential vitamin E and bone mineral depletion following ingestion. NTP conducted a 6-month study evaluated the effects of dietary chitosan on the development of osteopenia/osteoporosis, fat and calcium absorption, fat-soluble vitamin depletion, and general toxicity effects in Charles River Sprague Dawley rats.