# Appendix I Sentinel Animal Program

## I.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera from extra (sentinel) animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected from each rat and allowed to clot and the serum was separated. All samples were processed appropriately and tested for the presence of pathogens at BioReliance Corporation (Rockville, MD) or the Research Animal Diagnostic Laboratory (RADIL), University of Missouri, Columbia, MO. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five rats per sex per time point, except at study termination when blood was collected from four males and five females.

Table I-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
ELISA
Kilham rat virus (KRV) | 4 weeks
Pneumonia virus of mice (PVM) | End of quarantine, 4 weeks, study termination
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | End of quarantine, 4 weeks, study termination
Rat parvovirus (RPV) | 4 weeks
Sendai | End of quarantine, 4 weeks, study termination
Toolan’s H-1 virus (H-1) | 4 weeks
Immunofluorescence Assay
H-1 | 4 weeks
KRV | 4 weeks
Parvovirus | End of quarantine, 4 weeks, 6 weeks, study termination
RCV/SDA | End of quarantine
RPV | 4 weeks
Multiplex Fluorescent Immunoassay
H-1 | 6 weeks
KRV | 6 weeks
Parvo NS-1 | 6 weeks
Rat minute virus | 6 weeks
RPV | 6 weeks

## I.2 Results

A positive test result for parvovirus occurred in one animal at the 4-week timepoint; additional testing of serum from this animal and other sentinel animals via other testing methodologies deemed the original positive result to be a false positive. All other test results were negative for rodent pathogens.