# Appendix H Ingredients and Nutrient Composition in AIN-93M Maintenance Purified Diet

Table H-1 Ingredients of AIN-93M Maintenance Purified Rodent Diet

Ingredients | Percent by Weight
Corn starch | 46.5692
Dextrin | 15.5000
Casein (vitamin free) | 14.0000
Sucrose | 10.0000
Powdered cellulose | 5.0000
Soybean oil | 4.0000
AIN-93M mineral mix | 3.5000
AIN-93M vitamin mix | 1.0000
Choline bitartrate | 0.2500
L-Cystine | 0.1800
t-Butylhydroquinone | 0.0008

Table H-2 Vitamins, Minerals, and Nutrient Composition of AIN-93M Maintenance Purified Rodent Diet

| Amount
Vitamins
A | 4.00 IU/g
D_3_ (added) | 1.00 IU/g
E | 78.80 IU/g
K (as menadione) | 0.75 ppm
Thiamine hydrochloride | 6.00 ppm
Riboflavin | 6.50 ppm
Niacin | 30.00 ppm
Pantothenic acid | 16.00 ppm
Folic acid | 2.10 ppm
Pyridoxine | 5.80 ppm
Biotin | 0.20 ppm
B_12_ | 28.00 mcg/kg
Choline chloride | 1,250.00 ppm
Ascorbic acid | 0.00 ppm
Minerals
Calcium | 0.50%
Phosphorus | 0.31%
Potassium | 0.36%
Magnesium | 0.05%
Sodium | 0.13%
Chlorine | 0.20%
Fluorine | 1.00 ppm
Iron | 39.00 ppm
Zinc | 35.00 ppm
Manganese | 11.00 ppm
Copper | 6.00 ppm
Cobalt | 0.00 ppm
Iodine | 0.21 ppm
Chromium | 1.00 ppm
Molybdenum | 0.14 ppm
Selenium | 0.22 ppm
Typical Analysis
Protein | 13.06%
Fat | 4.00%
Fiber | 5.00%
Carbohydrate | 73.80%
Metabolizable energy | 3.83%