# Appendix G Feed and Compound Consumption in the Six-month Feed Study of Chitosan

Table G-1 Feed and Compound Consumption by Group A Male Rats in the Six-month Feed Study of Chitosan

Week | 0% | | 1% | | | 3% | | | 9%
Week | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 22.2 | 238 | 23.8 | 243 | 980 | 23.6 | 242 | 2,929 | 21.4 | 243 | 7,931
2 | 21.6 | 297 | 23.1 | 308 | 750 | 23.0 | 303 | 2,278 | 26.9 | 265 | 9,137
3 | 22.8 | 346 | 24.0 | 359 | 668 | 25.4 | 354 | 2,156 | 27.3 | 307 | 8,002
4 | 22.6 | 388 | 23.5 | 404 | 582 | 24.9 | 398 | 1,877 | 26.7 | 350 | 6,872
5 | 22.3 | 421 | 23.5 | 438 | 537 | 25.8 | 436 | 1,774 | 27.4 | 388 | 6,355
6 | 21.5 | 446 | 21.7 | 465 | 467 | 24.6 | 464 | 1,591 | 26.4 | 413 | 5,759
7 | 23.1 | 475 | 23.5 | 493 | 477 | 25.7 | 491 | 1,570 | 27.8 | 442 | 5,662
8 | 22.3 | 496 | 24.1 | 513 | 470 | 25.2 | 514 | 1,471 | 27.1 | 464 | 5,259
9 | 22.3 | 514 | 24.1 | 535 | 450 | 25.1 | 534 | 1,411 | 26.7 | 483 | 4,980
10 | 21.8 | 529 | 23.2 | 554 | 419 | 25.1 | 548 | 1,373 | 26.2 | 498 | 4,735
11 | 21.8 | 543 | 23.3 | 570 | 409 | 25.5 | 566 | 1,353 | 25.5 | 511 | 4,493
12 | 21.6 | 554 | 23.1 | 585 | 395 | 24.5 | 579 | 1,270 | 26.4 | 521 | 4,557
13 | 22.3 | 563 | 22.6 | 598 | 378 | 24.8 | 584 | 1,274 | 26.9 | 527 | 4,595
14 | 21.5 | 578 | 22.9 | 612 | 374 | 25.7 | 602 | 1,280 | 26.4 | 544 | 4,371
15 | 21.7 | 587 | 22.7 | 622 | 365 | 25.5 | 613 | 1,249 | 26.7 | 557 | 4,315
16 | 22.2 | 597 | 22.7 | 631 | 360 | 27.0 | 620 | 1,306 | 28.5 | 565 | 4,542
17 | 23.4 | 607 | 23.7 | 645 | 367 | 28.0 | 634 | 1,325 | 29.2 | 575 | 4,569
18 | 23.6 | 614 | 24.6 | 657 | 375 | 28.4 | 646 | 1,320 | 29.0 | 584 | 4,468
19 | 22.3 | 624 | 23.0 | 667 | 345 | 26.6 | 657 | 1,214 | 27.8 | 595 | 4,202
20 | 23.6 | 633 | 23.2 | 677 | 343 | 25.4 | 664 | 1,148 | 27.4 | 600 | 4,112
21 | 23.8 | 643 | 23.4 | 689 | 340 | 24.8 | 670 | 1,110 | 28.5 | 606 | 4,230
22 | 24.1 | 653 | 23.1 | 700 | 330 | 25.7 | 677 | 1,139 | 26.9 | 612 | 3,959
23 | 22.6 | 665 | 21.3 | 707 | 301 | 25.7 | 686 | 1,125 | 25.4 | 615 | 3,715
24 | 21.5 | 666 | 19.6 | 704 | 278 | 24.9 | 689 | 1,084 | 25.4 | 612 | 3,738
25 | 21.2 | | 20.4 | | | 24.7 | | | 27.3
Mean for Weeks
1–13 | 22.2 | 447 | 23.3 | 466 | 537 | 24.9 | 462 | 1,717 | 26.4 | 416 | 6,026
14–24 | 22.8 | 624 | 22.7 | 665 | 343 | 26.2 | 651 | 1,209 | 27.4 | 588 | 4,202

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of chitosan consumed per kilogram body weight per day.

Table G-2 Feed and Compound Consumption by Group A Female Rats in the Six-month Feed Study of Chitosan

Week | 0% | | 1% | | | 3% | | | 9%
Week | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 17.7 | 175 | 22.3 | 173 | 1,286 | 17.3 | 177 | 2,940 | 16.9 | 177 | 8,606
2 | 15.1 | 199 | 15.4 | 198 | 779 | 15.6 | 197 | 2,381 | 17.6 | 191 | 8,298
3 | 15.8 | 220 | 16.2 | 217 | 747 | 15.0 | 214 | 2,102 | 16.9 | 206 | 7,371
4 | 16.2 | 233 | 16.7 | 229 | 728 | 15.6 | 231 | 2,023 | 17.3 | 221 | 7,044
5 | 16.0 | 248 | 17.4 | 241 | 722 | 15.9 | 242 | 1,974 | 17.3 | 234 | 6,649
6 | 14.7 | 258 | 17.5 | 252 | 694 | 14.7 | 251 | 1,759 | 16.4 | 243 | 6,067
7 | 15.9 | 266 | 17.9 | 262 | 683 | 15.2 | 259 | 1,759 | 16.7 | 248 | 6,069
8 | 15.9 | 274 | 17.3 | 268 | 645 | 15.5 | 267 | 1,739 | 16.7 | 259 | 5,810
9 | 15.9 | 281 | 17.7 | 276 | 641 | 15.9 | 274 | 1,740 | 16.7 | 266 | 5,656
10 | 15.9 | 287 | 18.2 | 284 | 641 | 15.7 | 281 | 1,678 | 16.6 | 268 | 5,577
11 | 15.2 | 294 | 17.4 | 289 | 601 | 15.5 | 286 | 1,624 | 16.2 | 274 | 5,329
12 | 15.8 | 300 | 17.5 | 295 | 594 | 15.9 | 292 | 1,632 | 15.7 | 279 | 5,071
13 | 15.3 | 305 | 16.1 | 300 | 537 | 16.9 | 298 | 1,699 | 16.2 | 281 | 5,192
14 | 15.3 | 312 | 16.8 | 303 | 555 | 16.3 | 304 | 1,609 | 16.5 | 285 | 5,218
15 | 14.7 | 316 | 16.2 | 307 | 528 | 16.7 | 309 | 1,623 | 16.8 | 288 | 5,258
16 | 16.2 | 320 | 19.1 | 311 | 615 | 17.7 | 314 | 1,694 | 19.2 | 291 | 5,940
17 | 15.9 | 325 | 18.2 | 314 | 581 | 16.9 | 315 | 1,611 | 18.0 | 293 | 5,537
18 | 16.4 | 327 | 19.5 | 317 | 615 | 17.8 | 318 | 1,679 | 19.1 | 296 | 5,803
19 | 17.8 | 330 | 19.6 | 321 | 610 | 18.9 | 321 | 1,768 | 18.6 | 299 | 5,607
20 | 17.3 | 328 | 21.7 | 324 | 670 | 18.8 | 321 | 1,757 | 19.2 | 297 | 5,819
21 | 18.2 | 335 | 21.1 | 332 | 636 | 19.0 | 330 | 1,725 | 19.1 | 302 | 5,688
22 | 18.5 | 339 | 19.7 | 337 | 584 | 19.2 | 336 | 1,712 | 18.9 | 306 | 5,554
23 | 17.4 | 343 | 17.5 | 340 | 515 | 17.3 | 339 | 1,532 | 17.7 | 306 | 5,201
24 | 16.1 | 345 | 17.2 | 340 | 506 | 15.6 | 339 | 1,381 | 16.7 | 309 | 4,863
25 | 16.4 | | 20.3 | | | 17.1 | | | 18.8
Mean for Weeks
1–13 | 15.8 | 257 | 17.5 | 253 | 715 | 15.7 | 251 | 1,927 | 16.7 | 242 | 6,364
14–24 | 16.7 | 329 | 18.8 | 322 | 583 | 17.7 | 322 | 1,645 | 18.2 | 297 | 5,499

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of chitosan consumed per kilogram body weight per day.