# Appendix F Chemical Characterization and Dose Formulation Studies

## F.1 Procurement and Characterization of Chitosan

Chitosan was obtained from Vanson HaloSource, Inc. (Redmond, WA), in one lot (02-ASSF-0715), which was used in the 6-month study. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (MRI) (Kansas City, MO) and by the study laboratory at Battelle Columbus Operations (Columbus, OH). Reports on analyses performed in support of the chitosan studies are on file at the National Institute of Environmental Health Sciences.

The test article, an off-white powder, was identified as chitosan by the analytical chemistry laboratory using infrared (IR) and proton nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using IR spectroscopy. The percentage of deacetylation of the test article, determined by proton NMR, ranged from 85.97% to 87.17%, with an average of 86.5%. All spectra were consistent with the literature spectra,^38,39^ and with the Sadtler spectral database. Representative IR and NMR spectra are presented in Figure F-1 and Figure F-2, respectively.

The moisture content for lot 02-ASSF-0715 was determined by the analytical chemistry laboratory using weight loss on drying in a 110°C oven for 24 hours; the inorganic content was determined on the dried test article by ashing at 500°C for 4 hours. Viscosity was determined at approximately 22.5°C using a Brookfield viscometer fitted with an SC4-18/R13 spindle at a speed of 30 rpm. Lot 02-ASSF-0715 was characterized by the analytical chemistry laboratory using gel permeation chromatography (GPC) with refractive index (RI) detection using system A (Table F-1) to find the most abundant molecular weight. Samples were prepared by transferring approximately 75 mg of the test article into a vial, and adding a 25 mL aliquot of diluent; vials were sealed with Teflon^^®^^-lined septa and crimp caps, allowed to stand for 2 hours at ambient temperature, swirled by hand, and placed on a rotary shaker for at least 1 hour. Standards containing a total of six molecular weight dextran markers with known peak molecular weights (Mp) (4,400, 21,400, 43,500, 196,000, 277,000, and 3,900,000 Mp) were prepared; approximately 10 mg of each marker (3 mg of 3,900,000 Mp marker) and 10 mL of diluent were pipetted into vials, sealed with Teflon^^®^^-lined septa and crimp caps, allowed to stand for a least 2 hours (the 3,900,000 marker was allowed to stand overnight) at ambient temperature to dissolve the standards, then swirled to mix prior to analysis.

For lot 02-ASSF-0715, weight loss on drying indicated 4.50% water, the average inorganic content by ashing was determined to be 2.13%, and viscosity was 81.3 centipoise. GPC/RI indicated one major peak and the determined molecular weight of the bulk chemical ranged from 62,755 to 87,343 daltons (Da). This resulted in an average molecular weight of 81,644 g/mol, or approximately 82 kDa, classifying the test article as a low molecular weight chitosan (LMWCS). A sample of chitosan was submitted to Covance Laboratories, Inc. (Madison, WI), for nutritional and contaminant testing using standard methods. For lot 02-ASSF-0715, levels of organochlorine and organophosphorous pesticides, nitrosamines, and aflatoxins were below the detection limits of the analytical methods. The purity of lot 02-ASSF-0715 was estimated to be approximately 94% based on the analysis of moisture and inorganic content. Taken together, these data indicated that the test article was chitosan.

To ensure stability, the test article was stored in sealed amber glass vials at room temperature. Reanalysis of the test article was performed during the study by the study laboratory using GPC/RI by system B, and no degradation of the test article was detected.

## F.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared approximately monthly by mixing chitosan with feed (Table F-2). Dose formulations were stored in lined plastic buckets sealed with lids and stored at −30°C to −15°C for up to 42 days.

Homogeneity studies of approximately 0.5% and 9% formulations (5,046 and 90,049 µg/g, respectively) and stability studies of an approximately 0.5% (5,046 µg/g) formulation were performed by the analytical chemistry laboratory using GPC/RI by system C (Table F-1). Two peaks were attributed to chitosan with retention times of approximately 6.9 minutes and 12.1 minutes, respectively. Chitosan quantitation was based on the larger polymeric components of the first peak only because vehicle components co-eluted with the later oligomeric peak. Homogeneity studies of 1% and 9% dose formulations (10 mg/g and 90 mg/g in feed, respectively) were performed by the study laboratory using GPC/RI by system B. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in lined plastic buckets sealed with lids at temperatures up to room temperature and for at least 7 days under simulated animal room conditions.

Periodic analyses of the dose formulations of chitosan were performed by the study laboratory using GPC/RI by system B. Of the dose formulations analyzed, all nine were within 10% of the target concentrations (Table F-3). Animal room samples of dose formulations were also analyzed; all three were within 10% of the target concentrations.

Table F-1 Gel Permeation Chromatography Systems Used in the Six-month Feed Study of Chitosan^a^

Detection System | Column | Solvent System
System A
Refractive index | In series: NOVEMA 10,000 Å, 300 mm × 8 mm, 10 µm and NOVEMA 3,000 Å, 50 mm × 8 mm (guard) and NOVEMA 3,000 Å, 300 mm × 8 mm, 10 µm (Polymer Standards Service GmbH, Mainz, Germany) | 0.25% Trifluoroacetic acid, isocratic, flow rate 1.0 mL/minute
System B
Refractive index | In series: BioSep-SEC-S2000 145 Å, 300 mm × 4.6 mm, 5 µm and BioSep-SEC-S3000 290 Å, 300 mm × 4.6 mm, 5 µm (Phenomenex, Torrance, CA) | 1% Trifluoroacetic acid, isocratic, flow rate 0.35 mL/minute
System C
Refractive index | In series: Alltech^®^ Macrosphere 100 Å, 250 mm × 4.6 mm, 7 µm and Alltech^®^ Macrosphere 300 Å, 250 mm × 4.6 mm, 7 µm (Grace, Columbia, MD) | 1% Trifluoroacetic acid, isocratic, flow rate 0.5 mL/minute

^a^ The liquid chromatographs were manufactured by Waters Corporation (Milford, MA) (System A), Agilent (Palo Alto, CA) (System B), or Perkin Elmer (Boston, MA) (System C).

Table F-2 Preparation and Storage of Dose Formulations in the Six-month Feed Study of Chitosan

Six-month Feed Study
Preparation
The appropriate amounts of chitosan and AIN-93M feed (87 kg for 1% and 3% formulations and 79 kg for the 9% formulation) were weighed in tared stainless steel buckets and layered into a Patterson-Kelly twin-shell blender. The chitosan beaker was rinsed twice with portions of the blank feed, added to the blender, and the formulation was mixed for 15 minutes. The dose formulations were prepared approximately monthly.
Chemical Lot Number
02-ASSF-0715
Maximum Storage Time
42 days
Storage Conditions
Stored in plastic-lined 5 gallon plastic buckets sealed with lids at −30° to −15°C
Study Laboratory
Battelle Columbus Operations (Columbus, OH)

Table F-3 Results of Analyses of Dose Formulations Administered to Rats in the Six-month Feed Study of Chitosan

Date Prepared | Date Analyzed | Target Concentration^a^ (mg/g) | Determined Concentration^b^ (mg/g) | Difference from Target (%)
August 15, 2006 | August 17–18, 2006 | 10 | 9.1 | −10
| | 30 | 27.3 | −9
| | 90 | 83.5 | −7
| October 2–3, 2006^c^ | 10 | 9.99 | 0
| | 30 | 30.3 | +1
| | 90 | 92.4 | +3
October 10, 2006 | October 11–12, 2006 | 10 | 9.5 | −5
| | 30 | 27.0 | −10
| | 90 | 94.2 | +5
January 2, 2007 | January 2–3, 2007 | 10 | 10.6 | +6
| | 30 | 29.5 | −2
| | 90 | 94.3 | +5

^a^ 10, 30, and 90 mg/g are equivalent to 1%, 3%, and 9% chitosan concentrations, respectively.

^b^ Results of duplicate analyses.

^c^ Animal room samples.

Figure F-1

Infrared Absorption Spectrum of Chitosan

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of Chitosan