# Appendix E Reproductive Tissue Evaluations

Table E-1 Summary of Reproductive Tissue Evaluations for Group A Male Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 669 ± 20 | 702 ± 21 | 687 ± 23 | 612 ± 17
L. Cauda epididymis | 0.2013 ± 0.0073 | 0.2134 ± 0.0079 | 0.2281 ± 0.0167 | 0.2072 ± 0.0103
L. Epididymis | 0.6874 ± 0.0184 | 0.7047 ± 0.0274 | 0.7398 ± 0.0175 | 0.6402 ± 0.0165
L. Testis | 1.7349 ± 0.0423 | 1.8209 ± 0.0478 | 1.7922 ± 0.0619 | 1.7900 ± 0.0333
Spermatid measurements
Spermatid heads (10^6^/testis) | 207.79 ± 18.44 | 183.39 ± 9.19 | 238.70 ± 20.45 | 175.57 ± 8.43
Spermatid heads (10^6^/g testis) | 120.38 ± 11.23 | 101.50 ± 5.84 | 135.54 ± 14.11 | 98.05 ± 4.29
Epididymal spermatozoal measurements
Sperm motility (%) | 86.0 ± 0.37 | 86.1 ± 0.46 | 85.9 ± 0.46 | 85.8 ± 0.47
Sperm (10^6^/cauda epididymis) | 169.25 ± 14.82 | 182.38 ± 8.81 | 160.75 ± 12.63 | 157.63 ± 12.41
Sperm (10^6^/g cauda epididymis) | 833 ± 52 | 856 ± 33 | 711 ± 33 | 760 ± 46

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).