# Appendix D Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table D-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Group A Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
n | 10 | 10 | 10 | 10
Male
Necropsy body wt | 669 ± 20 | 702 ± 21 | 687 ± 23 | 612 ± 17
Heart
Absolute | 1.82 ± 0.07 | 1.81 ± 0.06 | 1.86 ± 0.08 | 1.77 ± 0.06
Relative | 2.723 ± 0.089 | 2.589 ± 0.070 | 2.710 ± 0.091 | 2.904 ± 0.085
R. Kidney
Absolute | 2.04 ± 0.04 | 2.04 ± 0.04 | 2.11 ± 0.06 | 1.88 ± 0.04*
Relative | 3.068 ± 0.088 | 2.920 ± 0.047 | 3.093 ± 0.088 | 3.093 ± 0.094
Liver
Absolute | 25.19 ± 0.87 | 24.87 ± 1.35 | 23.74 ± 1.51 | 19.53 ± 0.71**
Relative | 37.662 ± 0.731 | 35.321 ± 1.179 | 34.345 ± 1.411* | 31.933 ± 0.817**
Lung
Absolute | 2.49 ± 0.11 | 2.77 ± 0.09 | 2.62 ± 0.08 | 2.53 ± 0.14
Relative | 3.738 ± 0.163 | 3.949 ± 0.095 | 3.841 ± 0.138 | 4.120 ± 0.160
R. Testis
Absolute | 1.696 ± 0.054 | 1.778 ± 0.046 | 1.726 ± 0.062 | 1.750 ± 0.028
Relative | 2.555 ± 0.108 | 2.546 ± 0.078 | 2.534 ± 0.107 | 2.883 ± 0.104
Thymus
Absolute | 0.763 ± 0.045 | 0.727 ± 0.065 | 0.606 ± 0.063* | 0.489 ± 0.032**
Relative | 1.147 ± 0.071 | 1.030 ± 0.077 | 0.888 ± 0.091* | 0.797 ± 0.045**
Thyroid gland and parathyroid gland
Absolute | 0.033 ± 0.003 | 0.034 ± 0.002 | 0.034 ± 0.002 | 0.031 ± 0.002
Relative | 0.049 ± 0.004 | 0.048 ± 0.003 | 0.050 ± 0.003 | 0.051 ± 0.003
Parathyroid gland
Absolute | 0.0012 ± 0.0001 | 0.0010 ± 0.0001 | 0.0011 ± 0.0001 | 0.0011 ± 0.0001
Relative | 0.002 ± 0.000 | 0.001 ± 0.000 | 0.002 ± 0.000 | 0.002 ± 0.000
Female
Necropsy body wt | 338 ± 11 | 335 ± 13 | 328 ± 11 | 301 ± 13
Heart
Absolute | 1.14 ± 0.03 | 1.09 ± 0.02 | 1.15 ± 0.03 | 1.03 ± 0.02**
Relative | 3.393 ± 0.121 | 3.295 ± 0.094 | 3.515 ± 0.100 | 3.473 ± 0.134
R. Kidney
Absolute | 1.12 ± 0.04 | 1.10 ± 0.02 | 1.13 ± 0.03 | 1.01 ± 0.03
Relative | 3.311 ± 0.085 | 3.311 ± 0.095 | 3.465 ± 0.108 | 3.399 ± 0.104
Liver
Absolute | 12.54 ± 0.82 | 12.47 ± 0.39 | 11.85 ± 0.29 | 9.85 ± 0.20**
Relative | 36.900 ± 1.502 | 37.341 ± 0.444 | 36.346 ± 0.904 | 33.036 ± 0.910*
Lung
Absolute | 1.83 ± 0.06 | 1.80 ± 0.08 | 1.81 ± 0.05 | 1.65 ± 0.05
Relative | 5.463 ± 0.181 | 5.396 ± 0.170 | 5.552 ± 0.202 | 5.557 ± 0.281
R. Ovary
Absolute | 0.054 ± 0.005 | 0.049 ± 0.005 | 0.057 ± 0.005 | 0.056 ± 0.007
Relative | 0.161 ± 0.015 | 0.147 ± 0.015 | 0.179 ± 0.021 | 0.190 ± 0.026
Thymus
Absolute | 0.436 ± 0.033 | 0.400 ± 0.036 | 0.383 ± 0.023 | 0.302 ± 0.021**
Relative | 1.284 ± 0.081 | 1.188 ± 0.083 | 1.169 ± 0.062 | 1.000 ± 0.047**
Thyroid gland and parathyroid gland
Absolute | 0.028 ± 0.002 | 0.027 ± 0.002 | 0.035 ± 0.002 | 0.031 ± 0.002
Relative | 0.084 ± 0.005 | 0.082 ± 0.007 | 0.106 ± 0.007 | 0.104 ± 0.008
Parathyroid gland
Absolute | 0.0007 ± 0.0001 | 0.0009 ± 0.0001 | 0.0008 ± 0.0001 | 0.0008 ± 0.0001
Relative | 0.002 ± 0.000 | 0.003 ± 0.000* | 0.002 ± 0.000 | 0.003 ± 0.000*
Uterus
Absolute | 0.657 ± 0.052 | 0.744 ± 0.060 | 0.714 ± 0.038 | 0.789 ± 0.096
Relative | 1.980 ± 0.186 | 2.252 ± 0.191 | 2.184 ± 0.104 | 2.650 ± 0.329

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).