# Appendix C Vitamin Concentration and Bone Parameter Results

Table C-1 Serum and Hepatic Vitamin Concentration Data for Group B Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
Male
n
Week 7 | 9 | 10 | 10 | 10
Week 13 | 9 | 10 | 10 | 10
Week 19 | 9 | 10 | 10 | 10
Week 26 | 9 | 10 | 10 | 8
Serum vitamin A (µg/mL)
Week 7 | 0.532 ± 0.021 | 0.506 ± 0.033 | 0.513 ± 0.026 | 0.453 ± 0.018
Week 13 | 0.561 ± 0.024 | 0.499 ± 0.019 | 0.476 ± 0.022* | 0.410 ± 0.009**
Week 19 | 0.533 ± 0.028 | 0.506 ± 0.031 | 0.475 ± 0.019 | 0.392 ± 0.014**
Week 26 | 0.476 ± 0.019 | 0.444 ± 0.024 | 0.398 ± 0.017** | 0.336 ± 0.026**
Serum 1,25 (OH)_2_ vitamin D (pg/mL)
Week 7 | 124.4 ± 19.6 | 163.3 ± 21.7 | 183.2 ± 26.9 | 297.4 ± 41.0**
Week 13 | 70.1 ± 7.3 | 57.4 ± 5.3 | 77.3 ± 4.4 | 86.1 ± 8.5
Week 19 | 20.6 ± 2.8 | 21.7 ± 6.1 | 22.9 ± 2.2 | 42.3 ± 3.1**^b^
Week 26 | 27.7 ± 3.4^c^ | 28.0 ± 4.3 | 36.1 ± 4.6^b^ | 66.9 ± 11.9**
Serum vitamin E (µg/mL)
Week 7 | 19.33 ± 1.43 | 15.38 ± 1.29 | 12.92 ± 0.48** | 4.14 ± 0.23**
Week 13 | 21.08 ± 1.61 | 17.45 ± 1.06* | 12.27 ± 0.86** | 4.33 ± 0.27**
Week 19 | 20.59 ± 1.61 | 16.19 ± 0.96 | 12.86 ± 0.42** | 4.07 ± 0.32**
Week 26 | 19.66 ± 1.66 | 17.35 ± 1.37 | 12.35 ± 0.61** | 3.59 ± 0.65**
Liver vitamin A (µg/g)
Week 26 | 57.4 ± 17.6 | 29.9 ± 2.5 | 39.6 ± 3.1 | 31.4 ± 3.7
Liver vitamin E (µg/g)
Week 26 | 66.8 ± 16.2 | 55.0 ± 6.8 | 34.6 ± 2.2** | 8.5 ± 0.8**
Female
n
Week 7 | 10 | 10 | 10 | 10
Week 13 | 10 | 10 | 10 | 10
Week 19 | 10 | 10 | 10 | 10
Week 26 | 10 | 10 | 9 | 10
Serum vitamin A (µg/mL)
Week 7 | 0.272 ± 0.011 | 0.253 ± 0.007 | 0.260 ± 0.012 | 0.266 ± 0.012
Week 13 | 0.308 ± 0.020 | 0.295 ± 0.011 | 0.309 ± 0.019 | 0.281 ± 0.018
Week 19 | 0.283 ± 0.014 | 0.271 ± 0.015 | 0.291 ± 0.012 | 0.231 ± 0.010*
Week 26 | 0.316 ± 0.015 | 0.302 ± 0.014 | 0.294 ± 0.018 | 0.249 ± 0.010**
Serum 1,25 (OH)_2_ vitamin D (pg/mL)
Week 7 | 104.0 ± 15.1 | 96.7 ± 10.9 | 111.0 ± 8.7 | 208.1 ± 18.2**
Week 13 | 60.6 ± 7.5 | 60.7 ± 7.9 | 69.3 ± 11.0 | 110.1 ± 16.9
Week 19 | 11.6 ± 1.6 | 12.6 ± 1.7 | 15.8 ± 1.4 | 31.4 ± 3.2**
Week 26 | 19.2 ± 2.2 | 20.7 ± 4.2 | 28.6 ± 6.5 | 53.7 ± 5.8**
Serum vitamin E (µg/mL)
Week 7 | 18.65 ± 0.71 | 20.08 ± 0.87 | 18.38 ± 0.85 | 6.99 ± 0.58**
Week 13 | 19.81 ± 1.41 | 20.85 ± 1.06 | 20.19 ± 1.20 | 7.48 ± 0.38**
Week 19 | 21.02 ± 1.76 | 19.74 ± 1.75 | 19.86 ± 1.08 | 7.37 ± 0.57**
Week 26 | 20.94 ± 1.56 | 23.43 ± 1.66 | 22.23 ± 1.75 | 7.28 ± 0.64**
Liver vitamin A (µg/g)
Week 26 | 65.2 ± 5.4 | 58.9 ± 5.0 | 62.3 ± 6.3 | 60.3 ± 4.8
Liver vitamin E (µg/g)
Week 26 | 84.5 ± 8.9 | 97.1 ± 10.1 | 82.0 ± 11.8 | 17.2 ± 3.2**

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 7.

Table C-2 Bone Data for Groups A and B Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
n | 10 | 10 | 10 | 10
Male
Bone calcium (%) | 23.79 ± 0.21^b^ | 23.95 ± 0.22 | 23.92 ± 0.30 | 23.74 ± 0.11^c^
Bone ash (%) | 45.33 ± 0.79^b^ | 45.24 ± 0.67 | 45.83 ± 0.52 | 43.46 ± 0.62^c^
Bone moisture (%) | 29.90 ± 0.49^b^ | 30.30 ± 0.44 | 29.72 ± 0.36 | 31.79 ± 0.62^c^
Left femur length (mm) | 43.96 ± 0.34 | 44.33 ± 0.30 | 44.10 ± 0.30 | 43.42 ± 0.37
Left tibia length (mm) | 48.00 ± 0.37 | 48.27 ± 0.36 | 47.95 ± 0.37 | 47.57 ± 0.41
Right tibia length (mm) | 48.06 ± 0.32 | 48.41 ± 0.41 | 47.95 ± 0.33 | 47.57 ± 0.43
Female
Bone calcium (%) | 24.65 ± 0.17 | 24.96 ± 0.20 | 24.77 ± 0.23^b^ | 24.84 ± 0.12
Bone ash (%) | 47.07 ± 0.58 | 47.14 ± 0.57 | 47.44 ± 0.46^b^ | 45.87 ± 0.44
Bone moisture (%) | 28.40 ± 0.54 | 28.45 ± 0.45 | 28.53 ± 0.49^b^ | 30.37 ± 0.37**
Left femur length (mm) | 36.65 ± 0.21 | 36.75 ± 0.17 | 36.73 ± 0.28 | 36.37 ± 0.26
Left tibia length (mm) | 40.56 ± 0.28 | 40.25 ± 0.23 | 40.62 ± 0.40 | 40.10 ± 0.24
Right tibia length (mm) | 40.53 ± 0.30 | 40.42 ± 0.24 | 40.74 ± 0.42 | 40.12 ± 0.21

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data. Bone content data are from Group B rats at week 26 and bone lengths are from Group A rats at week 25.

^b^ n = 9.

^c^ n = 8.