# Appendix B Clinical Pathology Results

Table B-1 Hematology, Clinical Chemistry, and Urinalysis Data for Group C Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
Male
Hematology
n | 10 | 10 | 10 | 10
Hematocrit (auto) (%)
Week 25 | 45.5 ± 0.4 | 47.1 ± 0.5 | 46.3 ± 0.4 | 47.4 ± 0.6*
Hematocrit (manual) (%)
Week 25 | 47.2 ± 0.5^b^ | 48.2 ± 0.5 | 47.6 ± 0.5 | 48.9 ± 0.6
Hemoglobin (g/dL)
Week 25 | 14.9 ± 0.2 | 15.4 ± 0.2 | 15.2 ± 0.1 | 15.7 ± 0.2**
Erythrocytes (10^6^/μL)
Week 25 | 8.44 ± 0.08 | 8.59 ± 0.12 | 8.43 ± 0.08 | 8.45 ± 0.12
Reticulocytes (10^3^/μL)
Week 25 | 186.0 ± 14.3 | 138.4 ± 6.3** | 157.7 ± 7.2 | 139.3 ± 9.1**
Mean cell volume (fL)
Week 25 | 53.9 ± 0.4 | 54.9 ± 0.6 | 54.9 ± 0.2 | 56.1 ± 0.6*
Mean cell hemoglobin (pg)
Week 25 | 17.6 ± 0.2 | 18.0 ± 0.2 | 18.0 ± 0.1 | 18.6 ± 0.2**
Mean cell hemoglobin concentration (g/dL)
Week 25 | 32.7 ± 0.2 | 32.7 ± 0.1 | 32.9 ± 0.2 | 33.2 ± 0.2
Platelets (10^3^/μL)
Week 25 | 916 ± 52 | 824 ± 26 | 921 ± 19 | 973 ± 36
Leukocytes (10^3^/μL)
Week 25 | 10.62 ± 0.98 | 9.39 ± 0.94 | 7.38 ± 0.69 | 9.54 ± 0.91
Segmented neutrophils (10^3^/μL)
Week 25 | 2.04 ± 0.38 | 1.48 ± 0.24 | 1.06 ± 0.12 | 1.76 ± 0.39
Lymphocytes (10^3^/μL)
Week 25 | 8.02 ± 0.64 | 7.42 ± 0.74 | 6.01 ± 0.62 | 7.44 ± 0.65
Monocytes (10^3^/μL)
Week 25 | 0.31 ± 0.05 | 0.32 ± 0.05 | 0.20 ± 0.02 | 0.19 ± 0.03
Basophils (10^3^/μL)
Week 25 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.02 ± 0.00 | 0.03 ± 0.01
Eosinophils (10^3^/μL)
Week 25 | 0.21 ± 0.05 | 0.15 ± 0.03 | 0.09 ± 0.01* | 0.11 ± 0.03
Clinical Chemistry
n | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Week 25 | 12.4 ± 0.6 | 12.1 ± 0.5 | 12.7 ± 0.5 | 15.3 ± 0.9**
Creatinine (mg/dL)
Week 25 | 0.62 ± 0.01 | 0.64 ± 0.02 | 0.62 ± 0.01 | 0.64 ± 0.02
Calcium (mg/dL)
Week 13 | 12.6 ± 0.1 | 12.5 ± 0.1 | 12.3 ± 0.2 | 12.4 ± 0.2
Week 19 | 12.5 ± 0.1 | 12.3 ± 0.2 | 12.3 ± 0.1 | 12.0 ± 0.1*
Week 25 | 12.1 ± 0.1 | 12.1 ± 0.2 | 12.0 ± 0.1 | 11.6 ± 0.1*
Phosphorus (mg/dL)
Week 13 | 8.4 ± 0.3 | 8.1 ± 0.3 | 7.2 ± 0.3** | 7.4 ± 0.4*
Week 19 | 8.2 ± 0.4 | 7.7 ± 0.2 | 7.4 ± 0.3 | 6.7 ± 0.2**
Week 25 | 6.9 ± 0.3 | 6.8 ± 0.2 | 6.7 ± 0.1 | 5.8 ± 0.3**
Total protein (g/dL)
Week 25 | 7.4 ± 0.1 | 7.2 ± 0.1 | 7.3 ± 0.1 | 6.9 ± 0.1*
Albumin (g/dL)
Week 19 | 4.8 ± 0.1 | 4.6 ± 0.1 | 4.7 ± 0.1 | 4.5 ± 0.0*
Week 25 | 4.8 ± 0.1 | 4.7 ± 0.1 | 4.8 ± 0.1 | 4.6 ± 0.0
Cholesterol (mg/dL)
Week 7 | 82 ± 5 | 75 ± 8 | 80 ± 6 | 53 ± 3**
Week 13 | 95 ± 7 | 84 ± 8 | 90 ± 7 | 53 ± 2**
Week 19 | 101 ± 6 | 87 ± 10 | 94 ± 8 | 59 ± 4**
Week 25 | 95 ± 6 | 81 ± 8 | 90 ± 6 | 49 ± 4**
Triglycerides (mg/dL)
Week 7 | 202 ± 28 | 234 ± 43 | 226 ± 30 | 88 ± 15*
Week 13 | 198 ± 33 | 202 ± 38 | 195 ± 24 | 86 ± 8**
Week 19 | 180 ± 26 | 218 ± 43 | 210 ± 29 | 95 ± 13*
Week 25 | 173 ± 18 | 207 ± 30 | 218 ± 24 | 109 ± 13
Alanine aminotransferase (IU/L)
Week 25 | 28 ± 3 | 29 ± 2 | 29 ± 1 | 57 ± 2**
Alkaline phosphatase (IU/L)
Week 7 | 134 ± 7 | 134 ± 7 | 138 ± 8 | 137 ± 16
Week 13 | 100 ± 6 | 95 ± 6 | 102 ± 6 | 82 ± 5
Week 19 | 91 ± 11 | 87 ± 7 | 84 ± 4 | 72 ± 7
Week 25 | 85 ± 7 | 83 ± 7 | 82 ± 5 | 64 ± 5*
Creatine kinase (IU/L)
Week 25 | 192 ± 29 | 205 ± 27 | 233 ± 23 | 245 ± 20
Sorbitol dehydrogenase (IU/L)
Week 25 | 17 ± 3 | 17 ± 2 | 15 ± 1 | 14 ± 1
Bile acids (µmol/L)
Week 25 | 9.6 ± 2.3 | 6.4 ± 2.7 | 2.4 ± 0.2** | 4.3 ± 0.8
Total osteocalcin (ng/mL)
Week 7 | 445.7 ± 17.2 | 439.8 ± 15.8 | 441.8 ± 18.2 | 520.4 ± 22.6
Week 13 | 306.2 ± 13.0 | 289.7 ± 28.6 | 245.4 ± 37.9 | 372.6 ± 23.4
Week 19 | 239.4 ± 12.4 | 225.7 ± 10.6 | 181.6 ± 26.8 | 269.2 ± 20.9
Week 25 | 158.3 ± 10.0 | 168.1 ± 11.6 | 145.9 ± 22.7 | 218.3 ± 14.6*
Parathyroid hormone (ng/mL)
Week 7 | 1.882 ± 0.137 | 1.643 ± 0.449 | 1.838 ± 0.348 | 1.521 ± 0.368
Week 13 | 2.343 ± 0.350 | 2.763 ± 0.479 | 3.215 ± 0.537 | 2.433 ± 0.222
Week 19 | 1.879 ± 0.186 | 3.101 ± 0.475 | 2.710 ± 0.365 | 3.679 ± 0.361**
Week 25 | 2.668 ± 0.475 | 2.924 ± 0.276 | 3.981 ± 0.349 | 2.848 ± 0.506
Urinalysis
n
Week 7 | 10 | 9 | 10 | 10
Week 13 | 10 | 10 | 10 | 10
Week 19 | 10 | 10 | 10 | 10
Week 25 | 10 | 10 | 10 | 10
Creatinine (mg/dL)
Week 7 | 192.5 ± 15.1 | 227.2 ± 30.7 | 269.4 ± 33.6 | 254.9 ± 37.2
Week 13 | 249.4 ± 25.1 | 360.7 ± 19.5* | 350.3 ± 22.5* | 334.0 ± 35.8
Week 19 | 204.3 ± 20.4 | 394.2 ± 32.5** | 345.1 ± 26.0** | 302.5 ± 26.6
Week 25 | 254.1 ± 27.4 | 374.8 ± 25.6* | 345.9 ± 27.1 | 325.4 ± 36.0
Volume (mL)
Week 7 | 8.3 ± 0.8 | 7.5 ± 1.5 | 6.4 ± 0.8 | 5.0 ± 1.1*
Week 13 | 7.9 ± 1.0 | 4.6 ± 0.3** | 5.1 ± 0.4* | 4.5 ± 0.5**
Week 19 | 10.7 ± 1.6 | 4.0 ± 0.4** | 5.3 ± 0.7* | 5.6 ± 0.6
Week 25 | 8.6 ± 1.2 | 5.4 ± 0.6* | 6.1 ± 0.8* | 5.1 ± 0.6**
Deoxypyridinoline (nmol/L)
Week 7 | 3,396.0 ± 268.0 | 4,210.0 ± 643.0 | 4,917.0 ± 826.0 | 4,754.0 ± 761.0
Week 13 | 2,185.1 ± 188.9 | 3,197.3 ± 148.3* | 3,233.8 ± 218.0* | 3,129.1 ± 296.5*
Week 19 | 1,084.9 ± 158.9 | 2,209.6 ± 246.3** | 1,963.0 ± 200.5* | 1,994.9 ± 214.3*
Week 25 | 1,083.5 ± 145.9 | 1,699.3 ± 139.6* | 1,658.3 ± 136.7* | 1,750.8 ± 167.6*
Deoxypyridinoline/creatinine (nmol/mg)
Week 7 | 1.810 ± 0.135 | 1.889 ± 0.148 | 1.810 ± 0.159 | 1.920 ± 0.160
Week 13 | 0.910 ± 0.035 | 0.890 ± 0.031 | 0.930 ± 0.040 | 0.960 ± 0.078
Week 19 | 0.530 ± 0.050 | 0.550 ± 0.034 | 0.570 ± 0.042 | 0.660 ± 0.048
Week 25 | 0.430 ± 0.030 | 0.470 ± 0.030 | 0.480 ± 0.020 | 0.550 ± 0.027**
Female
Hematology
n | 10 | 9 | 10 | 10
Hematocrit (auto) (%)
Week 25 | 45.5 ± 1.0 | 44.9 ± 0.9 | 44.5 ± 0.8 | 45.2 ± 0.9
Hematocrit (manual) (%)
Week 25 | 47.4 ± 1.1 | 46.9 ± 1.0 | 46.5 ± 0.8 | 46.6 ± 0.9
Hemoglobin (g/dL)
Week 25 | 15.2 ± 0.4 | 15.0 ± 0.3 | 15.0 ± 0.3 | 15.1 ± 0.3
Erythrocytes (10^6^/μL)
Week 25 | 8.16 ± 0.19 | 8.17 ± 0.18 | 8.01 ± 0.11 | 8.10 ± 0.15
Reticulocytes (10^3^/μL)
Week 25 | 135.2 ± 14.6 | 109.2 ± 6.1 | 109.6 ± 7.7 | 129.5 ± 14.6
Mean cell volume (fL)
Week 25 | 55.8 ± 0.6 | 55.0 ± 0.3 | 55.6 ± 0.3 | 55.8 ± 0.8
Mean cell hemoglobin (pg)
Week 25 | 18.7 ± 0.2 | 18.4 ± 0.1 | 18.7 ± 0.1 | 18.7 ± 0.3
Mean cell hemoglobin concentration (g/dL)
Week 25 | 33.5 ± 0.1 | 33.4 ± 0.2 | 33.6 ± 0.2 | 33.4 ± 0.2
Platelets (10^3^/μL)
Week 25 | 791 ± 43 | 798 ± 40 | 848 ± 38 | 1,024 ± 51**
Leukocytes (10^3^/μL)
Week 25 | 6.62 ± 0.92 | 3.66 ± 0.49* | 5.72 ± 0.87 | 4.92 ± 0.58
Segmented neutrophils (10^3^/μL)
Week 25 | 1.15 ± 0.24 | 0.53 ± 0.10* | 0.67 ± 0.11 | 0.67 ± 0.11
Lymphocytes (10^3^/μL)
Week 25 | 5.09 ± 0.79 | 2.93 ± 0.41 | 4.78 ± 0.77 | 4.06 ± 0.49
Monocytes (10^3^/μL)
Week 25 | 0.24 ± 0.04 | 0.13 ± 0.02 | 0.18 ± 0.03 | 0.11 ± 0.02*
Basophils (10^3^/μL)
Week 25 | 0.02 ± 0.00 | 0.01 ± 0.00* | 0.02 ± 0.01 | 0.01 ± 0.00
Eosinophils (10^3^/μL)
Week 25 | 0.12 ± 0.02 | 0.06 ± 0.01 | 0.08 ± 0.01 | 0.07 ± 0.02
Clinical Chemistry
n
Week 7 | 10 | 10 | 10 | 10
Week 13 | 10 | 10 | 10 | 10
Week 19 | 10 | 10 | 10 | 10
Week 25 | 10 | 9 | 10 | 10
Urea nitrogen (mg/dL)
Week 25 | 14.2 ± 1.4 | 14.1 ± 0.7 | 15.2 ± 0.7 | 16.3 ± 0.7*
Creatinine (mg/dL)
Week 25 | 0.65 ± 0.02 | 0.68 ± 0.01 | 0.70 ± 0.01 | 0.69 ± 0.02
Calcium (mg/dL)
Week 13 | 12.9 ± 0.2 | 13.1 ± 0.1 | 12.7 ± 0.2 | 12.5 ± 0.2
Week 19 | 12.9 ± 0.1 | 13.1 ± 0.2 | 12.8 ± 0.1 | 12.5 ± 0.1
Week 25 | 12.7 ± 0.3 | 12.8 ± 0.1 | 12.7 ± 0.2 | 12.3 ± 0.2
Phosphorus (mg/dL)
Week 13 | 8.1 ± 0.5 | 7.4 ± 0.4 | 6.5 ± 0.4** | 6.8 ± 0.3*
Week 19 | 8.4 ± 0.4 | 8.2 ± 0.5 | 8.1 ± 0.3 | 7.4 ± 0.5
Week 25 | 6.8 ± 0.2 | 6.4 ± 0.2 | 6.2 ± 0.3* | 5.5 ± 0.3**
Total protein (g/dL)
Week 25 | 8.2 ± 0.2 | 9.0 ± 0.1** | 8.6 ± 0.2 | 8.4 ± 0.2
Albumin (g/dL)
Week 19 | 5.9 ± 0.2 | 6.2 ± 0.1 | 5.9 ± 0.2 | 5.7 ± 0.1
Week 25 | 5.8 ± 0.2 | 6.5 ± 0.2* | 6.2 ± 0.1 | 6.2 ± 0.1
Cholesterol (mg/dL)
Week 7 | 80 ± 6 | 81 ± 8 | 67 ± 4 | 59 ± 4**
Week 13 | 92 ± 8 | 86 ± 7 | 73 ± 5 | 58 ± 4**
Week 19 | 107 ± 7 | 105 ± 9 | 91 ± 8 | 67 ± 5**
Week 25 | 94 ± 7 | 108 ± 5 | 96 ± 8 | 63 ± 4**
Triglycerides (mg/dL)
Week 7 | 88 ± 12 | 130 ± 48 | 81 ± 8 | 86 ± 14
Week 13 | 125 ± 10 | 163 ± 30 | 140 ± 23 | 88 ± 23*
Week 19 | 143 ± 15 | 181 ± 32 | 137 ± 18 | 90 ± 13
Week 25 | 188 ± 31 | 231 ± 44 | 245 ± 31 | 158 ± 35
Alanine aminotransferase (IU/L)
Week 25 | 25 ± 3 | 28 ± 3 | 32 ± 2** | 47 ± 4**
Alkaline phosphatase (IU/L)
Week 7 | 102 ± 7 | 99 ± 5 | 99 ± 7 | 95 ± 10
Week 13 | 57 ± 4 | 63 ± 4 | 71 ± 7 | 59 ± 5
Week 19 | 49 ± 5 | 53 ± 3 | 55 ± 6 | 46 ± 6
Week 25 | 46 ± 4 | 44 ± 2 | 51 ± 6 | 44 ± 7
Creatine kinase (IU/L)
Week 25 | 258 ± 44 | 193 ± 46 | 210 ± 50 | 225 ± 26
Sorbitol dehydrogenase (IU/L)
Week 25 | 17 ± 3 | 17 ± 2 | 19 ± 2 | 16 ± 1
Bile acids (µmol/L)
Week 25 | 10.7 ± 1.8 | 8.2 ± 1.1 | 32.0 ± 14.1 | 10.8 ± 1.1
Total osteocalcin (ng/mL)
Week 7 | 293.6 ± 19.4 | 287.5 ± 21.2 | 282.1 ± 34.7 | 316.7 ± 23.5
Week 13 | 197.9 ± 22.6 | 202.3 ± 15.4 | 184.4 ± 19.4 | 234.2 ± 14.5
Week 19 | 158.1 ± 18.3 | 184.8 ± 13.2 | 166.7 ± 24.7 | 210.1 ± 16.0
Week 25 | 107.9 ± 18.6 | 97.1 ± 7.1 | 96.0 ± 16.2 | 148.8 ± 15.1
Parathyroid hormone (ng/mL)
Week 7 | 0.995 ± 0.150^b^ | 1.156 ± 0.176 | 1.092 ± 0.182 | 1.023 ± 0.146
Week 13 | 1.506 ± 0.203 | 1.734 ± 0.194 | 1.925 ± 0.306 | 1.767 ± 0.212
Week 19 | 1.406 ± 0.232 | 1.994 ± 0.353 | 1.845 ± 0.418 | 1.673 ± 0.223
Week 25 | 1.471 ± 0.189^b^ | 1.628 ± 0.220 | 1.818 ± 0.224 | 2.301 ± 0.212*
Urinalysis
n
Week 7 | 10 | 10 | 10 | 10
Week 13 | 10 | 10 | 10 | 10
Week 19 | 10 | 10 | 10 | 10
Week 25 | 10 | 9 | 10 | 9
Creatinine (mg/dL)
Week 7 | 98.2 ± 14.7 | 107.1 ± 12.3 | 206.3 ± 55.2* | 192.0 ± 8.3**
Week 13 | 144.7 ± 14.8 | 139.5 ± 15.9 | 247.5 ± 30.9* | 241.6 ± 29.0**
Week 19 | 142.0 ± 19.7 | 137.7 ± 19.4 | 196.3 ± 23.6 | 230.3 ± 19.2**
Week 25 | 179.8 ± 59.7 | 120.3 ± 24.1 | 184.5 ± 20.5 | 217.9 ± 23.4*
Volume (mL)
Week 7 | 8.2 ± 1.2 | 8.5 ± 1.0 | 5.4 ± 0.8 | 3.4 ± 0.3**
Week 13 | 6.4 ± 0.7 | 6.5 ± 0.6 | 4.1 ± 0.8* | 2.9 ± 0.5**
Week 19 | 7.7 ± 1.2 | 8.1 ± 1.4 | 5.0 ± 0.8 | 3.4 ± 0.5**
Week 25 | 8.2 ± 1.5 | 9.1 ± 1.5 | 5.8 ± 0.9 | 3.7 ± 0.5**
Deoxypyridinoline (nmol/L)
Week 7 | 1,622.0 ± 328.0 | 1,378.0 ± 295.0 | 4,130.0 ± 1,109.0* | 4,423.0 ± 355.0**
Week 13 | 875.5 ± 129.6 | 587.0 ± 68.1 | 1,364.0 ± 215.9 | 1,421.6 ± 267.0
Week 19 | 666.3 ± 106.9 | 487.7 ± 68.5 | 894.9 ± 122.1 | 1,212.3 ± 107.4**
Week 25 | 565.7 ± 178.2 | 250.4 ± 47.1 | 625.1 ± 83.7 | 891.5 ± 114.1*
Deoxypyridinoline/creatinine (nmol/mg)
Week 7 | 1.620 ± 0.128 | 1.240 ± 0.129 | 1.940 ± 0.229 | 2.300 ± 0.182*
Week 13 | 0.580 ± 0.039 | 0.430 ± 0.037** | 0.540 ± 0.034 | 0.570 ± 0.042
Week 19 | 0.450 ± 0.017 | 0.360 ± 0.016* | 0.440 ± 0.016 | 0.520 ± 0.020
Week 25 | 0.340 ± 0.043 | 0.222 ± 0.022 | 0.340 ± 0.027 | 0.411 ± 0.026

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.