# Appendix A Summary of Lesions in Rats in the Six-month Feed Study of Chitosan

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Group A Male Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Degeneration, cystic | 0 | 0 | 0 | 1 (10%)
Hematopoietic cell proliferation | 2 (20%) | 3 (30%) | 3 (30%) | 6 (60%)
Inflammation, chronic active | 10 (100%) | 10 (100%) | 10 (100%) | 9 (90%)
Periportal, fatty change | 6 (60%) | 3 (30%) | 6 (60%) | 3 (30%)
Pancreas | (10) | (0) | (0) | (10)
Basophilic focus | 1 (10%) | – | – | 0
Inflammation | 2 (20%) | – | – | 1 (10%)
Stomach, forestomach | (10) | (0) | (0) | (10)
Epithelium, hyperplasia | 3 (30%) | – | – | 1 (10%)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (10)
Inflammation | 0 | – | – | 1 (10%)
Heart | (10) | (0) | (0) | (10)
Cardiomyopathy | 5 (50%) | – | – | 3 (30%)
Mineralization | 0 | – | – | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (1) | (0) | (10)
Vacuolization cytoplasmic | 0 | 0 | – | 1 (10%)
Parathyroid gland | (10) | (10) | (10) | (10)
Hyperplasia | 1 (10%) | 0 | 0 | 0
Pituitary gland | (10) | (0) | (0) | (10)
Cyst | 1 (10%) | – | – | 0
Thyroid gland | (10) | (0) | (0) | (10)
C-cell, hyperplasia | 0 | – | – | 1 (10%)
General Body System
None | – | – | – | –
Genital System
Preputial gland | (10) | (0) | (0) | (10)
Inflammation | 0 | – | – | 1 (10%)
Inflammation, chronic active | 0 | – | – | 2 (20%)
Prostate | (10) | (10) | (10) | (10)
Inflammation | 8 (80%) | 9 (90%) | 10 (100%) | 10 (100%)
Testes | (10) | (0) | (0) | (10)
Mineralization | 0 | – | – | 1 (10%)
Hematopoietic System
Lymph node, mandibular | (10) | (0) | (0) | (10)
Infiltration cellular, plasma cell | 1 (10%) | – | – | 2 (20%)
Spleen | (10) | (0) | (0) | (10)
Hematopoietic cell proliferation | 5 (50%) | – | – | 2 (20%)
Thymus | (10) | (0) | (0) | (10)
Atrophy | 1 (10%) | – | – | 0
Integumentary System
Skin | (10) | (0) | (0) | (10)
Hemorrhage | 0 | – | – | 1 (10%)
Mineralization | 0 | – | – | 1 (10%)
Ulcer | 0 | – | – | 1 (10%)
Musculoskeletal System
Skeletal muscle | (0) | (0) | (0) | (1)
Inflammation, granulomatous | – | – | – | 1 (100%)
Nervous System
None | – | – | – | –
Respiratory System
Lung | (10) | (0) | (0) | (10)
Hemorrhage | 2 (20%) | – | – | 0
Inflammation, chronic active | 2 (20%) | – | – | 4 (40%)
Nose | (10) | (0) | (0) | (10)
Inflammation | 1 (10%) | – | – | 0
Goblet cell, hyperplasia | 0 | – | – | 1 (10%)
Special Senses System | – | – | –
Eye | (10) | (1) | (0) | (10)
Choroid, fibrosis | 0 | 1 (100%) | – | 0
Lens, cataract | 0 | 1 (100%) | – | 0
Harderian gland | (10) | (0) | (0) | (10)
Hyperplasia | 0 | – | – | 1 (10%)
Infiltration cellular, lymphocyte | 2 (20%) | – | – | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Infarct | 0 | 0 | 1 (10%) | 0
Mineralization | 2 (20%) | 4 (40%) | 3 (30%) | 5 (50%)
Nephropathy | 9 (90%) | 9 (90%) | 9 (90%) | 9 (90%)
Cortex, cyst | 1 (10%) | 0 | 0 | 0
Pelvis, dilatation | 2 (20%) | 0 | 1 (10%) | 0
Pelvis, inflammation | 1 (10%) | 0 | 0 | 0
Urinary bladder | (10) | (0) | (0) | (10)
Transitional epithelium, hyperplasia | 0 | – | – | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Group A Female Rats in the Six-month Feed Study of Chitosan^a^

| 0% | 1% | 3% | 9%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 1 (10%) | 1 (10%) | 2 (20%) | 1 (10%)
Inflammation, chronic active | 9 (90%) | 9 (90%) | 9 (90%) | 10 (100%)
Periportal, fatty change | 7 (70%) | 4 (40%) | 4 (40%) | 0
Pancreas | (10) | (0) | (0) | (10)
Atrophy | 0 | – | – | 1 (10%)
Inflammation | 1 (10%) | – | – | 0
Inflammation, chronic active | 0 | – | – | 1 (10%)
Cardiovascular System
Heart | (10) | (0) | (0) | (10)
Cardiomyopathy | 1 (10%) | – | – | 0
Endocrine System
Pituitary gland | (10) | (0) | (0) | (10)
Rathke’s cleft, hyperplasia | 1 (10%) | – | – | 0
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (10) | (0) | (0) | (10)
Inflammation, chronic active | 2 (20%) | – | – | 0
Hematopoietic System
Spleen | (10) | (0) | (0) | (10)
Hematopoietic cell proliferation | 1 (10%) | – | – | 0
Thymus | (10) | (0) | (0) | (10)
Atrophy | 1 (10%) | – | – | 0
Integumentary System
Mammary gland | (10) | (0) | (0) | (10)
Adenoma | 0 | – | – | 1 (10%)
Musculoskeletal System
None | – | – | – | –
Nervous System
Brain | (10) | (0) | (0) | (10)
Developmental malformation | 1 (10%) | – | – | 0
Respiratory System
Lung | (10) | (0) | (0) | (10)
Mineralization | 0 | – | – | 1 (10%)
Alveolar epithelium, hyperplasia | 0 | – | – | 1 (10%)
Alveolus, infiltration cellular, histiocyte | 2 (20%) | – | – | 0
Artery, mineralization | 1 (10%) | – | – | 1 (10%)
Nose | (10) | (0) | (0) | (10)
Goblet cell, hyperplasia | 1 (10%) | – | – | 0
Special Senses System
Harderian gland | (10) | (0) | (0) | (10)
Infiltration cellular, lymphocyte | 1 (10%) | – | – | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Mineralization | 8 (80%) | 8 (80%) | 5 (50%) | 6 (60%)
Nephropathy | 5 (50%) | 6 (60%) | 5 (50%) | 0

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.