# Peer Review

The draft NTP Technical Report on the Toxicity Studies of Octahydro-tetramethyl-naphthalenyl-ethanone (OTNE) Administered Dermally to F344/NTac Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this Toxicity Study Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Laura A. Hanson, Ph.D.
  Director, Molecular Mechanisms of Carcinogenesis Program
  Creighton University School of Medicine
  Omaha, Nebraska, USA
- Greg Erexson, Ph.D.
  Principal Occupational and Environmental Toxicologist
  AbbVie
  North Chicago, Illinois, USA