# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  K.R. Ryan, Ph.D., Study Scientist
  R.A. Herbert, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  D.R. Germolec, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- BioReliance Corporation, Rockville, Maryland, USA
  Conducted studies and evaluated pathology findings
  M.L. Wenk, Ph.D., Principal Investigator
  M. Paranjpe, D.V.M., Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  E.T. Adams, D.V.M., Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group (March 10, 2011)
  K.R. Hobbie, D.V.M., Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Provided andrology analyses
  R.W. Tyl, Ph.D., Principal Investigator
- Southern Research Institute, Birmingham, Alabama, USA
  Provided vaginal cytology analyses
  C.D. Hébert, Ph.D., Principal Investigator
  E. Mylchreest, Ph.D.