# References

1 Belsito D Bickers D Bruze M Calow P Dagli ML Fryer AD Greim H Miyachi Y Saurat JH Sipes IG. A toxicological and dermatological assessment of alkyl cyclic ketones when used as fragrance ingredients. Food Chem Toxicol. 2013; 62 Suppl 1:S1–S44. http://dx.doi.org/10.1016/j.fct.2013.09.033 24246175
2 Politano VT Letizia CS Christian MS Diener RM Api AM Evaluation of the developmental toxicity of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthalenyl) ethanone (OTNE) in rats. Int J Toxicol. 2009; 28(3):213–218. http://dx.doi.org/10.1177/1091581809335862 19546259
3 Wishneff J. Letter from Director, Government Affairs and Counsel, of International Fragrance Association North America to Dr. Maria Doa, regarding the response to EPA’s 2012 TSCA work plan chemicals: CASRN: 54464-57-2; 54464-59-4; 68155-66-8; 68155-67-9 dated August 31, 2012. http://www.regulations.gov/#!documentDetail;D=EPA-HQ-OPPT-2011-0516-0020 (click on comment) [Accessed: September 11, 2013]
4 Scognamiglio J Letizia CS Politano VT Api AM Fragrance material review on 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthalenyl)ethanone (OTNE). Food Chem Toxicol. 2013; 62 Suppl 1:S120–S132. http://dx.doi.org/10.1016/j.fct.2013.08.056 24246180
5 Fahlbusch K, Hammerschmidt F, Panten J, Pickenhagen W, Schatkowski D, Bauer K, Garbe D, Surburg H. Flavors and fragrances In: Ullmann’s Encyclopedia of Industrial Chemistry, 7th ed, Sections 1.5.1-1.5.2. Wiley-VCH Verlag GmbH & Co., KgaA; 2003. http://dx.doi.org/10.1002/14356007.a11_141
6 United States Environmental Protection Agency (USEPA). Non-confidential 2006 IUR records by chemical, including manufacturing, processing and use information. CAS: 54464-57-2. 2010. https://www.epa.gov/chemical-data-reporting/downloadable-2006-iur-public-database [Accessed: September 11, 2013]
7 United States Environmental Protection Agency (USEPA). Non-confidential 2006 IUR records by chemical, including manufacturing, processing and use information. CAS: 68155-67-9. 2010. https://www.epa.gov/chemical-data-reporting/downloadable-2006-iur-public-database [Accessed: September 11, 2013]
8 United States Environmental Protection Agency (USEPA). Non-confidential 2006 IUR records by chemical, including manufacturing, processing and use information. CAS: 68155-66-8. 2010. https://www.epa.gov/chemical-data-reporting/downloadable-2006-iur-public-database [Accessed: September 11, 2013]
9 Yin J Wang H Zhang J Zhou N Gao F Wu Y Xiang J Shao B The occurrence of synthetic musks in human breast milk in Sichuan, China. Chemosphere. 2012; 87(9):1018–1023. http://dx.doi.org/10.1016/j.chemosphere.2011.11.068 22196088
10 Kubwabo C Fan X Rasmussen PE Wu F Determination of synthetic musk compounds in indoor house dust by gas chromatography-ion trap mass spectrometry. Anal Bioanal Chem. 2012; 404(2):467–477. http://dx.doi.org/10.1007/s00216-012-6124-2 22684881
11 Bester K Klasmeier J Kupper T Emissions of OTNE (Iso-E-super) - mass flows in sewage treatment plants. Chemosphere. 2008; 71(11):2003–2010. http://dx.doi.org/10.1016/j.chemosphere.2008.02.004 18359059
12 Klaschka U von der Ohe PC Bschorer A Krezmer S Sengl M Letzel M Occurrences and potential risks of 16 fragrances in five German sewage treatment plants and their receiving waters. Environ Sci Pollut Res Int. 2013; 20(4):2456–2471. http://dx.doi.org/10.1007/s11356-012-1120-9 22945655
13 Simonich SL Begley WM Debaere G Eckhoff WS Trace analysis of fragrance materials in wastewater and treated wastewater. Environ Sci Technol. 2000; 34(6):959–965.http://dx.doi.org/10.1021/es991018g
14 United States Environmental Protection Agency (USEPA). TSCA work plan for chemical assessments: 2012. Washington, DC: US Environmental Protection Agency, Office of Pollution Prevention and Toxics; 2012. https://web.archive.org/web/20120316163830/http://www.epa.gov/oppt/existingchemicals/pubs/Work_Plan_Chemicals_Web_Final.pdf [Accessed: March 11, 2015]
15 United States Environmental Protection Agency (USEPA). TSCA work plan for chemical assessments: 2014 update. Washington, DC: US Environmental Protection Agency, Office of Pollution Prevention and Toxics; 2014. https://web.archive.org/web/20150419054002/http://www.epa.gov/oppt/existingchemicals/pubs/TSCA_Work_Plan_Chemicals_2014_Update-final.pdf [Accessed: March 11, 2015]
16 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1 (1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8 tetramethyl-2-naphthyl) ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key basic toxicokinetics.001. Study report, 2001-10-01. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-ad2f646c-2f3d-4148-bdd1-077723ea48d3_DISS-a001d05a-8c59-0cab-e04400144f67d031.html#AGGR-ad2f646c-2f3d-4148-bdd1-077723ea48d3 [Accessed: September 12, 2013]
17 Waidyanatha S Ryan K Disposition of fragrance ingredient [14C]1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthalenyl)ethanone in male Fisher rats following oral administration and dermal application. Xenobiotica. 2014; 44(8):749–756. http://dx.doi.org/10.3109/00498254.2014.888489 24533629
18 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key dermal absorption.001. Study report, 2001-01-04. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-70883983-bb18-4318-a52d-f5fed32b1e10_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-70883983-bb18-4318-a52d-f5fed32b1e10 [Accessed: September 12, 2013]
19 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key acute toxicity: oral.001. Study report, 1980-08-29. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-cbb53c2a-6567-4566-ac7c-120d3f7c8f63_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-cbb53c2a-6567-4566-ac7c-120d3f7c8f63 [Accessed: September 12, 2013]
20 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key acute toxicity: dermal.001. Study report, 1980-08-29. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044 00144f67d031/AGGR-fd7ec48a-ec1d-4378-9fa0-87f99335e98f_DISS-a001d05a-8c59-0cab-e0440144f67d031.html#AGGR-fd7ec48a-ec1d-4378-9fa0-87f99335e98f [Accessed: September 12, 2013]
21 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key repeated dose toxicity: oral.001. Study report, 1997-10-12. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-8c7e47a4-b969-4bd1-8606-02eb2f6d1f72_DISS-a001d05a-8c59-0cab-e04400144f67d031.html#AGGR-8c7e47a4-b969-4bd1-8606-02eb2f6d1f72 [Accessed: September 12, 2013]
22 National Toxicology Program (NTP). NTP report on the assessment of contact hyper-sensitivity to iso-E super in female BALB/c mice (CASRN: 54464-57-2). Research Triangle Park, NC: National Institute of Environmental Health Science; 2010. Report Number: IMM20702.
23 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key skin sensitisation.001. Study report, 2008-07-30. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-93d75f77-896b-43cb-9336-227c780478fb_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-93d75f77-896b-43cb-9336-227c780478fb [Accessed: September 12, 2013]
24 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp NS skin sensitisation.003. Study report, 2008-07-30. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-ef39d1f0-064d-49c3-9e56-f9583df0b585_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-ef39d1f0-064d-49c3-9e56-f9583df0b585 [Accessed: September 12, 2013]
25 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp NS skin sensitisation.004. Study report, 2005-11-09. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-413b6384-5dce-40a2-a590-c6f8a066cc43_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-413b6384-5dce-40a2-a590-c6f8a066cc43 [Accessed: September 12, 2013]
26 Frosch PJ Pilz B Andersen KE Burrows D Camarasa JG Dooms-Goossens A Ducombs G Fuchs T Hannuksela M Lachapelle JM Patch testing with fragrances: Results of a multicenter study of the European Environmental and Contact Dermatitis Research Group with 48 frequently used constituents of perfumes. Contact Dermat. 1995; 33(5):333–342. http://dx.doi.org/10.1111/j.1600-0536.1995.tb02048.x 8565489
27 Frosch PJ Johansen JD Menné T Pirker C Rastogi SC Andersen KE Bruze M Goossens A Lepoittevin JP White IR Further important sensitizers in patients sensitive to fragrances. Contact Dermat. 2002; 47(2):78–85. 12423404
28 Larsen W Nakayama H Fischer T Elsner P Frosch P Burrows D Jordan W Shaw S Wilkinson J Marks JFragrance contact dermatitis: a worldwide multicenter investigation (Part II). Contact Dermat. 2001; 44(6):344–346. http://dx.doi.org/10.1034/j.1600-0536.2001.044006344.x 11380544
29 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp NS skin irritation/corrosion.002. Study report, 2004-10-03. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-8053966f-162e-4bc6-8f4b-79b43a4cef90_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-8053966f-162e-4bc6-8f4b-79b43a4cef90 [Accessed: September 12, 2013]
30 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp NS skin sensitisation.002.Study report, 2004-06-24. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-e895e29d-7a39-418d-a142-7f05e7f435fa_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-e895e29d-7a39-418d-a142-7f05e7f435fa [Accessed: September 12, 2013]
31 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key skin irritation/corrosion.001. Study report, 2010-09-16. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-0c30a54f-3d41-4673-b1b7-4336690b0ea8_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-0c30a54f-3d41-4673-b1b7-4336690b0ea8 [Accessed: May 28, 2013]
32 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp supporting toxicity to reproduction: other studies.001. Study report, 2002-11-20. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-57d3ac43-af43-49f9-9738-ff58b21765c3_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-57d3ac43-af43-49f9-9738-ff58b21765c3 [Accessed: September 12, 2013]
33 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key genetic toxicity in vitro.003. Study report, 1997-10-07. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-d71efec5-1810-4f2b-b765-48fa0c31e7e7_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-d71efec5-1810-4f2b-b765-48fa0c31e7e7 [Accessed: September 12, 2013]
34 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key genetic toxicity in vitro.001. Study report, 1997-08-11. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-7df5870e-c2d8-46d7-8d79-08c5db840c1c_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-7df5870e-c2d8-46d7-8d79-08c5db840c1c [Accessed: September 12, 2013]
35 European Chemicals Agency (ECHA). Registered substances database: REACH (Registration, Evaluation, Authorisation and Restriction of Chemicals): Reaction mass of 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one and 1 (1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one: Exp key genetic toxicity in vitro.002. Study report, 2010 [date not provided]. 2013. http://apps.echa.europa.eu/registered/data/dossiers/DISS-a001d05a-8c59-0cab-e044-00144f67d031/AGGR-eca5ba36-e259-4635-9223-c7d2b48cfaf7_DISS-a001d05a-8c59-0cab-e044-00144f67d031.html#AGGR-eca5ba36-e259-4635-9223-c7d2b48cfaf7 [Accessed: September 12, 2013]
36 Erman M Williams M Whelan P Cardenas C Antipin M The composition of Iso E Super. Perfum Flavor. 2001; 26(2):16–21.
37 King-Herbert A Thayer K NTP workshop: Animal models for the NTP rodent cancer bioassay: stocks and strains—should we switch? Toxicol Pathol. 2006; 34(6):802–805. http://dx.doi.org/10.1080/01926230600935938 17162538
38 Cederbaum AI Role of CYP2E1 in ethanol-induced oxidant stress, fatty liver and hepatotoxicity. Dig Dis. 2010; 28(6):802–811. http://dx.doi.org/10.1159/000324289 21525766
39 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
40 Boorman GA Montgomery CA Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
41 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
42 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.http://dx.doi.org/10.1080/01621459.1955.10501294
43 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
44 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
45 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
46 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
47 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.http://dx.doi.org/10.1080/00401706.1964.10490181
48 Jonckheere A A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41:133–145.http://dx.doi.org/10.1093/biomet/41.1-2.133
49 Dixon W Massey F Introduction to statistical analysis. New York (NY): McGraw Hill Book Company Inc; 1957.http://dx.doi.org/10.2307/2332898
50 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. http://dx.doi.org/10.2307/2531963 3567307
51 Wilcoxon F. Individual comparisons by ranking methods. Biometrics Bull. 1945; 1(6):80-83. http://dx.doi.org/10.2307/3001968
52 Code of Federal Regulations (CFR). 21:Part 58.
53 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. http://dx.doi.org/10.1002/em.2850190603 1541260
54 Dertinger SD Camphausen K Macgregor JT Bishop ME Torous DK Avlasevich S Cairns S Tometsko CR Menard C Muanza T Three-color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. http://dx.doi.org/10.1002/em.20075 15517570
55 MacGregor JT Bishop ME McNamee JP Hayashi M Asano N Wakata A Nakajima M Saito J Aidoo A Moore MM Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: II. An efficient method of monitoring chromosomal damage in the rat. Toxicol Sci. 2006; 94(1):92–107. http://dx.doi.org/10.1093/toxsci/kfl076 16888079
56 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. http://dx.doi.org/10.1016/j.mrgentox.2007.08.004 17869571
57 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. http://dx.doi.org/10.1016/j.mrgentox.2007.07.010 17851117
58 Hampton AL Hish GA Aslam MN Rothman ED Bergin IL Patterson KA Naik M Paruchuri T Varani J Rush HG Progression of ulcerative dermatitis lesions in C57BL/6Crl mice and the development of a scoring system for dermatitis lesions. J Am Assoc Lab Anim Sci. 2012; 51(5):586–593. 23312087