# Discussion

OTNE is classified as an unsaturated alkyl cyclic ketone fragrance ingredient commonly referred to by the commercial name Iso-E Super^®^. Similar to other fragrance materials, OTNE is used as a perfume ingredient in soaps, shampoos, colognes, liquid detergent compounds, and malodor-reducing compounds including fabric freshening compounds, antiperspirants or deodorants, and air freshening compounds. Exposure to OTNE by the general public is primarily through dermal absorption and inhalation from products that contain the ingredient. It is estimated that OTNE is typically less than 1% in individual consumer household products with the exception of fine fragrances that may have up to 20% OTNE.^3,4^ The predicted human dermal exposure is calculated to be 0.4604 mg/kg body weight per day.^4^

OTNE toxicity data is summarized in REACH Dossiers in the European Chemicals Agency (ECHA) database and in a review by the Research Institute for Fragrance Materials^4^; however, the full reports of these toxicity studies are not publicly available. In these summaries, there is no mention of any subchronic or chronic toxicity studies of OTNE in rodents. The current Toxicity Study Report describes the 3-month toxicity studies of OTNE administered to F344/NTac rats and B6C3F1/N mice by dermal absorption which is the primary route of human exposure. OTNE is considered to have minimal acute toxicity in rats (dermal and oral LD_50_ > 5 g/kg).^4^ For sufficient hazard characterization in these studies, neat OTNE (100%) was applied dermally as the highest achievable concentration to rats and mice and corresponds to approximately 500 mg OTNE/kg body weight per day and 2,000 mg/kg per day, respectively. OTNE was dissolved in 95% aqueous ethanol to achieve lower concentrations of 6.25%, 12.5%, 25%, and 50% OTNE. Because the 100% OTNE animals did not receive ethanol, two control groups were included in the study design. For the untreated controls, animals were handled similarly but did not receive any treatment at the site of application, whereas the vehicle control animals received 95% ethanol at the site of application. The untreated controls served as a comparison for the 100% OTNE group, and the vehicle controls were used for comparing data from the 6.25% to 50% OTNE groups. Statistical comparisons between control groups were conducted, and no biologically relevant differences were observed (data not shown) suggesting that dermal exposure of ethanol over this time did not interfere with our assessment of OTNE toxicity.

Results of the current 3-month studies demonstrated that the skin at the site of application was considered the primary target of OTNE toxicity across both sexes and species. Mortality was not observed in either sex or species. Small but significant decreases in body weights were observed in male mice. Organ weight changes (absolute and relative) were observed at the end of the studies; some of the organ weight changes were accompanied by histopathologic lesions.

The majority of nonneoplastic lesions following the 3-month dermal exposure of OTNE occurred in the skin at the site of application of rats and mice. In general, hyperplasia and hyperkeratosis were observed in both sexes and both species. However, the incidences and the severities of these lesions were greater in male and female mice than in rats. Incidences of minimal to mild hyperplasia and hyperkeratosis were significantly increased in rats administered 12.5% OTNE or greater, whereas minimal to moderate hyperplasia and hyperkeratosis were observed in nearly all dosed groups of male and female mice. Furthermore, hyperplasia and hyperkeratosis in mice were accompanied by increased incidences of minimal to mild chronic active inflammation, fibrosis, epidermis suppurative inflammation, and hair follicle hyperplasia. These lesions also extended to the skin adjacent to the site of application in male and female mice and were considered secondary to the spread of the test material from the site of application rather than the result of a systemic OTNE effect. One likely explanation for the species differences in skin lesion incidences and severities is the applied dose. On a mg/kg body weight basis, as noted above, mice received doses of OTNE approximately four times higher than rats in this study. Another possibility is that mice on a C57BL/6 background have an increased susceptibility to idiopathic, spontaneous ulcerative dermatitis,^58^ and this increased susceptibility may have made the mice more sensitive to the irritating effects of OTNE and consequently exacerbated the severity of the skin lesions.

The skin lesions observed in the current studies have not previously been reported in the OTNE literature. However, these skin lesions were consistent with reports from a 3-month dermal study with a similar fragrance chemical, acetyl cedrene. The study summary available in Belsito et al.^1^ highlights that dosed rats administered acetyl cedrene [0 (water), 50, 150, or 300 mg/kg body weight per day] had evidence of skin irritation, mild chronic inflammation, and hyperkeratosis. Although the full study report is not publicly available for a side-by-side comparison with the current subchronic dermal studies, this information suggests that long-term use of fragrance compounds with an alkyl cyclic ketone structure has the potential for chronic toxicity to the skin.

The skin lesions observed in the current studies in rats and mice after dermal exposure for 3 months are consistent with evidence from human and animal irritation and sensitization studies. Previously, NTP concluded that OTNE was an irritant and had the potential to induce skin sensitization in female BALB/c mice examined in a combined local lymph node (LLNA) and irritancy assay.^22^ In this study, all mice treated with OTNE (0.5% to 50%) demonstrated significant irritation at the site of application. In the LLNA study, significant increases in lymph node cell proliferation were observed at concentrations of 25% and 50% only, suggesting that the positive response in this assay is a nonspecific response due to the irritant effect of the chemical. Variable results have been reported with regard to the ability of OTNE to act as a sensitizer and/or an irritant, as summarized in a review from the Research Institute for Fragrance Materials^4^ and also in the ECHA database. For example, OTNE was classified as a skin sensitizer in CBA/J mice following application of 2.5% to 50% OTNE.^23-25^ Conversely, in guinea pig and rabbit primary irritation studies, OTNE did not produce irritation in multiple acute tests at applied doses of less than 5%.^4^ In repeated application studies, 2.5% OTNE in ethanol caused skin irritation in guinea pigs.^1^ While the majority of human repeated insult patch tests indicated that OTNE is not a skin irritant, irritancy was observed in human volunteers administered OTNE at concentrations greater than 12.5% in two cases.^1^ It is difficult to determine the reason for the variable responses in these studies; however, it appears that both dose and frequency of exposure may play a role.

In male and female rats, treatment-related increases in absolute and relative liver weights were observed. Increases were significant in the 50% and 100% OTNE groups. This finding was consistent with a previous summary report demonstrating increased liver weights in rats administered 1,000 mg OTNE/kg body weight by gavage for 4 weeks.^21^ In that same report, increased liver weights were associated with centrilobular hepatocyte enlargement. However, histologic changes were not observed in the livers of rats following dermal application of OTNE for 3 months in the current study. The lack of histologic findings in the rat liver may be due to the route of administration (oral versus dermal) as well as dose; the highest dose administered in the current study was approximately 500 mg/kg.

In the current studies, dose-related increases in the absolute and relative liver weights of male and female mice were also observed, and the increases (ranging from 62% to 92% above controls) were significant in males treated with 12.5% OTNE or greater and all dosed female groups. Unlike rats treated with OTNE, increased liver weights in dosed mice were accompanied by minimal induction of cytochrome P4502E1 (Cyp2e1) activities and an increased incidence of centrilobular hypertrophy in males administered 100% OTNE. These species differences may be attributed to the fact that mice were treated with four times more OTNE on a mg/kg per day basis. Although statistically significant, the magnitudes of the Cyp2e1 activity increases were less than twofold in both male and female mice and may have marginally contributed to the increased liver weights or the increased incidence of centrilobular hypertrophy. Collectively, increased liver weights accompanied by increased Cyp2e1 activities and mild histopathologic changes indicate that dermal exposure to OTNE has the potential to cause some systemic toxicity. Although OTNE was administered dermally in the current studies, some oral exposure was anticipated based on animal grooming^17^ and could have contributed to the observed systemic toxicity in the liver. In a review of industry studies with several alkyl cyclic ketone fragrance compounds, the liver has been a common target (increased organ weights and some evidence of minimal hepatocyte hypertrophy) in several animal studies where compounds were administered dermally or by the oral route.^1^ These changes were reported to occur at high doses and were considered adaptive by the authors.

Other organ weight changes were observed in the current studies in the high dose groups (100% OTNE) of rats and mice. In rats, a small but significant increase in relative kidney weights was observed in the 100% OTNE male and female dose groups. Kidney lesions were not observed by histopathology in this study. However, eosinophilic inclusions in kidney cortical tubules of male rats, treated for 4 weeks with 150 or 1,000 mg/kg OTNE by gavage, were reported elsewhere.^21^ Likewise, the kidney has been reported as a target for toxicity in subacute and subchronic rat studies following exposure to various other alkyl cyclic ketone fragrance compounds.^1^ In mice, 100% OTNE elicited small but significant decreases in male and female thymus weights, although histopathologic changes were not observed and the toxicologic relevance of these weight changes is not known.

OTNE exposure via dermal application exhibited the potential to be a reproductive toxicant in male and female B6C3F1/N mice, but not in F344/NTac rats, as evidenced by fewer sperm, lower sperm motility, and alterations in estrous cyclicity. Recent reviews summarizing the toxicology information on OTNE (and other similar fragrance compounds) have not reported any toxicologic effects in rat reproductive tissues. Toxicity studies in mice that have included these endpoints are limited.^1,4^ Nevertheless, the differential response observed between species reported here may be the result of mice receiving a higher dose compared to rats.

In studies performed by NTP, OTNE was not mutagenic in vitro. This finding is consistent with industry studies demonstrating that OTNE was negative in bacterial mutagenicity tests and in mouse lymphoma L5178Y tk+/- cells treated with OTNE.^33,34^ Additionally, many other structurally related, unsaturated ketone fragrances have been found to be nonmutagenic in vitro.^1^ OTNE was considered negative for chromosomal aberrations when tested in human lymphocytes.^34^ However, in the NTP 3-month in vivo studies, OTNE was equivocal in male mice and positive in female mice in the micronucleus assay, which detects clastogenic and aneugenic events. These findings were based on statistically significant increases in the frequency of micronucleated mature erythrocytes in 100% OTNE male mice and, in female mice, dose-dependent increases in micronucleated mature erythrocytes and an increase in mature erythrocytes in a single-dose experiment with 100% OTNE, all of which reached statistical significance. It should be noted, however, that the statistically significant effects detected in dosed male and female mice were very small increases compared to the vehicle controls or untreated controls, which calls into question their biological significance. OTNE was negative for the micronucleus assay in male and female F344/NTac rats. Overall, this is the first study to suggest that repeated dermal application of OTNE may have genotoxic effects.

Under the conditions of these 3-month dermal studies, the major target in F344/NTac rats and B6C3F1/N mice was the skin, site of application. Lesions were more prominent in mice than rats based upon the incidences and severities of hyperplasia, hyperkeratosis, and inflammation of the skin, site of application. Additionally, hepatic lesions were apparent in mice, but not rats. OTNE exhibited the potential to be a reproductive toxicant in male and female mice. These species differences could be attributed to dose, because mice received approximately four times the amount of OTNE on a mg/kg body weight basis than rats. In male and female rats, the lowest-observed-effect level (LOEL) of 12.5% OTNE was based on the increased incidences of skin lesions. In male and female mice, the LOEL was 6.25% OTNE, based on the increased incidences of skin lesions and increased relative liver weights.