# Results

## Three-month Study in Rats

All rats survived to the end of the study (Table 3). Mean body weights and body weight gains of dosed (except 100% OTNE) males and females were similar to those of the respective control groups. The mean body weight gain of 100% OTNE males was significantly less than that of the untreated control group (Table 3 and Figure 2). There were no biologically significant clinical findings related to OTNE administration.

Table 3 Survival and Body Weights of Rats in the Three-month Dermal Study of OTNE^a^

Dose (%) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls^c^ (%)
Male
Untreated control | 10/10 | 86 ± 2 | 324 ± 6 | 239 ± 6
Vehicle control | 10/10 | 85 ± 2 | 318 ± 6 | 233 ± 5
6.25 | 10/10 | 83 ± 2 | 308 ± 9 | 225 ± 9 | 97
12.5 | 10/10 | 83 ± 2 | 293 ± 5 | 210 ± 5 | 92
25 | 10/10 | 84 ± 2 | 307 ± 8 | 223 ± 7 | 97
50 | 10/10 | 83 ± 2 | 302 ± 7 | 219 ± 7 | 95
100 | 10/10 | 86 ± 2 | 306 ± 7 | 219 ± 7^†^ | 94
Female
Untreated control | 10/10 | 82 ± 2 | 184 ± 4 | 102 ± 3
Vehicle control | 10/10 | 83 ± 1 | 187 ± 3 | 104 ± 2
6.25 | 10/10 | 82 ± 2 | 188 ± 2 | 106 ± 2 | 101
12.5 | 10/10 | 83 ± 2 | 184 ± 4 | 102 ± 4 | 99
25 | 10/10 | 84 ± 1 | 187 ± 4 | 103 ± 3 | 100
50 | 10/10 | 83 ± 1 | 184 ± 3 | 101 ± 2 | 99
100 | 10/10 | 82 ± 2 | 180 ± 3 | 98 ± 2 | 98

^†^ Significantly different (P ≤ 0.05) from the untreated control group by a t-test.

^a^ Weights and weight changes are given as mean ± standard error. Differences between the 6.25%, 12.5%, 25%, and 50% OTNE groups and the vehicle control groups are not significant by Dunnett’s test. Statistical comparisons between the two control groups are not presented.

^b^ Number of animals surviving to the end of the study/number initially in group.

^c^ Dosed groups are compared to the vehicle control groups, except 100% OTNE groups are compared to the untreated control groups.

Figure 2

Growth Curves for Rats Exposed to OTNE by Dermal Application for Three Months

There were no changes in the hematology parameters attributable to the dermal administration of OTNE (Table B-1). Serum alkaline phosphatase activities were decreased in various male and female dosed groups at all time points (days 3 and 23 and week 13). While this change was not always observed in the lower dosed groups, decreases were consistently observed in 100% OTNE males and females at all time points compared to the untreated control groups. At the end of the study (week 13), alanine aminotransferase activities were decreased in 25% OTNE or greater females and in all dosed groups of males compared to their respective control groups. The significance of these decreases is not known but may be related to an alteration in liver metabolism. Other changes in clinical chemistry results were not considered toxicologically or biologically relevant.

Mean microsomal protein yields and cytochrome P4502E1 (Cyp2e1) activities were measured on day 23 and at the end of the study (week 13) to distinguish between ethanol-related liver effects and the treatment-related effects of OTNE (Table B-2). Microsomal protein was significantly increased (up to 44%) at the end of the study in females from the 12.5% to 100% OTNE groups when compared to their respective controls. Microsomal protein (males) at week 13 and Cyp2e1 activities in the males and females were not statistically different from controls.

Absolute and relative liver weights were significantly greater (up to 30%) in the males and females of the 50% and 100% OTNE groups (except for the absolute liver weight of 50% males) with respect to their controls (Table 4 and Table C-1). Relative kidney weights were significantly increased by approximately 9% in the male and female rats of the 100% OTNE groups compared to untreated controls (Table C-1). Treatment-related histopathologic changes were not observed in the liver or kidney of males or females (Table A-1 and Table A-2).

Table 4 Liver Weights and Liver-Weight-to-Body-Weight Ratios for Rats in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
n | 10 | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 324 ± 6 | 318 ± 6 | 308 ± 9 | 293 ± 5 | 307 ± 8 | 302 ± 7 | 306 ± 7
Liver
Absolute | 13.62 ± 0.54 | 13.60 ± 0.48 | 12.81 ± 0.44 | 12.73 ± 0.50 | 13.33 ± 0.46 | 14.57 ± 0.74 | 15.93 ± 0.65^†^
Relative | 41.95 ± 1.17 | 42.77 ± 1.16 | 41.62 ± 0.95 | 43.55 ± 1.84 | 43.48 ± 1.38 | 48.04 ± 1.64* | 52.12 ± 1.83^††^
Female
Necropsy body wt | 184 ± 4 | 187 ± 3 | 188 ± 2 | 184 ± 4 | 187 ± 4 | 184 ± 3 | 180 ± 3
Liver
Absolute | 6.50 ± 0.33 | 6.99 ± 0.21 | 6.89 ± 0.19 | 7.09 ± 0.27 | 7.51 ± 0.20 | 7.78 ± 0.27*^b^ | 8.24 ± 0.18^††^
Relative | 35.29 ± 1.42 | 37.44 ± 0.67 | 36.60 ± 0.92 | 38.52 ± 1.40 | 40.09 ± 0.65 | 41.93 ± 1.35**^b^ | 46.29 ± 1.02^††^

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s or Williams’ test.

** P ≤ 0.01.

^†^ Significantly different (P ≤ 0.05) from the untreated control group by a t-test.

^††^ P ≤ 0.01.

^a^ Liver weights (absolute weights) and body weights are given in grams; liver-weight-to-body-weight ratios (relative weights) are given as mg liver weight/g body weight (mean ± standard error). Statistical comparisons between the two control groups are not presented.

^b^ n = 9.

Male rats did not display any OTNE-related changes in testis and epididymis weights or sperm parameters (Table D-1). Female rats administered OTNE did not display any toxicologically significant effects on cycle length, or estrous cyclicity (Table D-2).

In males and females administered 12.5% to 50% OTNE, the incidences of minimal to mild hyperplasia and hyperkeratosis (except 12.5% OTNE males) in the skin (site of application) were significantly greater than those of the vehicle control groups; the incidences of these lesions in 100% OTNE males and females were significantly greater than the untreated control incidences (Table 5, Table A-1, and Table A-2). Hyperplasia was characterized by variably thickened epidermis compared to that of the controls (Figure 4 and Figure 5) due to increased numbers of basal, squamous, and/or granular epidermal cells (Figure 6 and Figure 7). Hyperplasia was graded by the following criteria: minimal (2 to 3 cell layers thick); mild (3 to 4 cell layers thick); moderate (>5 cell layers thick without rete pegs); and marked (>5 cell layers thick with rete pegs). Hyperkeratosis was characterized by the presence of subtle to minimal compressed keratin overlying the stratum granulosum (Figure 6 and Figure 7).

Table 5 Incidences of Nonneoplastic Lesions of the Skin (Site of Application) in Rats in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Male
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Hyperkeratosis^b^ | 0 | 0 | 1 (1.0)^c^ | 3 (1.0) | 4* (1.0) | 5* (1.0) | 8^††^ (1.1)
Hyperplasia | 0 | 0 | 2 (1.0) | 4* (1.0) | 5* (1.0) | 8** (1.5) | 10^††^ (1.3)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Hyperkeratosis | 0 | 0 | 0 | 4* (1.0) | 5* (1.4) | 7** (1.3) | 7^††^ (1.9)
Hyperplasia | 0 | 0 | 1 (1.0) | 5* (1.0) | 7** (1.3) | 7** (1.4) | 8^††^ (1.9)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^††^ Significantly different (P ≤ 0.01) from the untreated control group by the Fisher exact test.

^a^ Statistical comparisons between the two control groups are not presented.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 4

Normal Epidermis (Arrows) in the Skin (Site of Application) of a Vehicle Control Female F344/NTac Rat in the Three Month Dermal Study of OTNE (H&E)

Figure 5

Higher Magnification of Figure 4 (H&E)

Normal epidermis (arrows) consists of a single layer of squamous epithelium that is slightly keratinized.

Figure 6

Mild Hyperplasia (Long Arrows) and Hyperkeratosis (Short Arrows) in the Skin (Site of Application) of a Female F344/NTac Rat Dermally Administered 100% OTNE for Three Months (H&E)

Compared to Figure 4, the epidermis and keratin layers appear thickened.

Figure 7

Higher Magnification of Figure 6 (H&E)

Compared to Figure 5, the granular cell layer (stratum granulosum) of the epidermis is thickened (hyperplasia) due to an increased number of cell layers (long arrows). Epidermal hyperplasia is accompanied by hyperkeratosis (short arrows) that consists of mild thickening of the keratin layer (stratum corneum).

## Three-month Study in Mice

All mice survived to the end of the study (Table 6). The final mean body weights of 6.25%, 25%, and 50% OTNE males and mean body weight gains of 6.25% and 25% OTNE males were significantly less than those of the vehicle control group; those of 100% OTNE males were significantly less than those of the untreated controls (Table 6 and Figure 3). Clinically, irritation was observed in the skin (site of application) of four males and two females administered 50% OTNE and in all males and females administered 100% OTNE. In addition, lesions considered to be ulcers were observed at the site of application in five males and two females administered 100% OTNE; these lesions were observed between day 43 in males and day 57 in females until the end of the study.

Table 6 Survival and Body Weights of Mice in the Three-month Dermal Study of OTNE^a^

Dose (%) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls^c^ (%)
Male
Untreated control | 10/10 | 23.1 ± 0.6 | 37.7 ± 1.2 | 14.6 ± 1.1
Vehicle control | 10/10 | 23.7 ± 0.2 | 35.0 ± 0.6 | 11.3 ± 0.6
6.25 | 10/10 | 22.9 ± 0.3 | 32.2 ± 0.4** | 9.3 ± 0.3* | 92
12.5 | 10/10 | 23.4 ± 0.3 | 33.7 ± 1.0 | 10.3 ± 0.8 | 96
25 | 10/10 | 22.6 ± 0.3 | 32.0 ± 0.4** | 9.4 ± 0.3* | 92
50 | 10/10 | 22.8 ± 0.5 | 32.5 ± 0.5* | 9.6 ± 0.4 | 93
100 | 10/10 | 23.1 ± 0.2 | 32.2 ± 0.4^††^ | 9.1 ± 0.4^††^ | 86
Female
Untreated control | 10/10 | 18.6 ± 0.3 | 28.5 ± 0.7 | 9.9 ± 0.5
Vehicle control | 10/10 | 19.1 ± 0.6 | 29.5 ± 0.7 | 10.4 ± 0.5
6.25 | 10/10 | 18.8 ± 0.3 | 30.1 ± 0.7 | 11.3 ± 0.7 | 102
12.5 | 10/10 | 18.8 ± 0.2 | 29.2 ± 0.6 | 10.4 ± 0.5 | 99
25 | 10/10 | 18.5 ± 0.2 | 28.9 ± 0.3 | 10.4 ± 0.3 | 98
50 | 10/10 | 18.4 ± 0.3 | 29.2 ± 0.4 | 10.8 ± 0.4 | 99
100 | 10/10 | 18.4 ± 0.2 | 29.4 ± 0.3 | 11.1 ± 0.3 | 103

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

** P ≤ 0.01.

^††^ Significantly different (P ≤ 0.01) from the untreated control group by a t-test.

^a^ Weights and weight changes are given as mean ± standard error. Statistical comparisons between the two control groups are not presented.

^b^ Number of animals surviving at the end of the study/number initially in group.

^c^ Dosed groups are compared to the vehicle control groups, except 100% OTNE groups are compared to the untreated control groups.

Figure 3

Growth Curves for Mice Exposed to OTNE by Dermal Application for Three Months

When compared to the vehicle (dosed groups) or untreated (100% OTNE groups) controls, significant decreases (≤14%) in the erythrocyte counts, hemoglobin concentrations, and hematocrit values occurred in the 25% OTNE or greater males and 100% OTNE females (Table B-3). Erythrocyte distribution widths, coefficients of variation of erythrocyte volumes (i.e., increased values indicate increased variation in sizes), were significantly increased in the 25% OTNE or greater males and in all dosed groups of females compared to their respective control groups. The parameters of erythrocyte count, hemoglobin concentration, and hematocrit value are quantitative estimates of the circulating erythroid mass. The changes in these parameters, paired with the changes in the red cell distribution width, were consistent with an alteration in erythropoiesis. Other changes in the erythron were not considered toxicologically or biologically relevant.

In male and female vehicle control mice at the end of the study, there was no effect on CYP2E1 activity relative to the untreated controls (Table B-4). This suggests that the vehicle itself did not affect liver function. However, male and female mice did exhibit dose-dependent increases in CYP2E1 activity. Male mice treated with 25%, 50%, or 100% OTNE had significantly increased CYP2E1 activities (ranging from 35% to 80%) when compared to their respective control groups. CYP2E1 activity was also significantly increased (ranging from 26% to 65%) in all female groups administered OTNE compared to their respective control groups. These increases in CYP2E1 activity were less than twofold and not considered biologically relevant.

Absolute and relative organ weights were significantly changed in male and female mice. Absolute liver weights of all female and all male dosed groups (except 6.25% OTNE males) were increased (up to 92%) compared to their respective controls (Table 7 and Table C-2). Similarly, the relative liver weights of all male and female dosed groups were increased (up to 89%) compared to their respective controls. Absolute and relative heart weights were increased approximately 14% in the 50% and 100% OTNE females; the relative heart weights of 25% and 100% OTNE males were also increased, but this may be due to the decreased body weights noted in the males (Table 6 and Table C-2). The absolute thymus weights of males and females as well as the relative thymus weight of females were decreased by approximately 22% in the 100% OTNE groups compared to untreated controls (Table C-2). In males, the absolute testis weight was decreased by 10% in the 50% OTNE group. In females, the relative lung weight of the 100% OTNE group was decreased by 21% compared to untreated controls. Histopathologic changes were not associated with alterations in organ weights, with the exception of centrilobular hypertrophy noted in 100% OTNE males (Table A-3, Table A-4, and Table C-2).

Table 7 Liver Weights and Liver-Weight-to-Body-Weight Ratios for Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
n | 10 | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 37.7 ± 1.2 | 35.0 ± 0.6 | 32.2 ± 0.4** | 33.7 ± 1.0 | 32.0 ± 0.4** | 32.5 ± 0.5* | 32.2 ± 0.4^††^
Liver
Absolute | 1.64 ± 0.05 | 1.60 ± 0.05 | 1.68 ± 0.07 | 1.82 ± 0.09* | 1.99 ± 0.09** | 2.12 ± 0.03** | 2.66 ± 0.07^††^
Relative | 43.79 ± 1.34 | 45.72 ± 1.29 | 51.98 ± 1.96* | 54.09 ± 2.20** | 62.10 ± 2.99** | 65.35 ± 1.52** | 82.51 ± 1.92^††^
Female
Necropsy body wt | 28.5 ± 0.7 | 29.5 ± 0.7 | 30.1 ± 0.7 | 29.2 ± 0.6 | 28.9 ± 0.3 | 29.2 ± 0.4 | 29.4 ± 0.3
Liver
Absolute | 1.28 ± 0.04 | 1.37 ± 0.05 | 1.52 ± 0.04* | 1.65 ± 0.04** | 1.69 ± 0.03** | 2.04 ± 0.05** | 2.46 ± 0.07^††^
Relative | 45.04 ± 1.03 | 46.48 ± 1.46 | 50.45 ± 0.76* | 56.53 ± 1.22** | 58.35 ± 0.61** | 69.96 ± 1.26** | 83.54 ± 2.31^††^

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s or Williams’ test.

** P ≤ 0.01.

^††^ Significantly different (P ≤ 0.01) from the untreated control group by a t-test.

^a^ Liver weights (absolute weights) and body weights are given in grams; liver-weight-to-body-weight ratios (relative weights) are given as mg liver weight/g body weight (mean ± standard error). Statistical comparisons between the two control groups are not presented.

Male mice administered 100% OTNE displayed fewer caudal sperm and caudal sperm/mg; these findings were not associated with any histopathologic changes in the testes or epididymides (Table 8, Table A-3, and Table D-3). Male mice in the 100% OTNE group also exhibited lower sperm motility (~11%) (Table 8 and Table D-3).

Table 8 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 25% | 50% | 100%
n | 9 | 10 | 7 | 7 | 10
Weights (g)
Necropsy body wt | 37.8 ± 1.3 | 35.0 ± 0.6 | 32.2 ± 0.5** | 32.9 ± 0.5* | 32.2 ± 0.4^††^
L. Cauda epididymis | 0.0210 ± 0.0015 | 0.0196 ± 0.0011 | 0.0218 ± 0.0017 | 0.0252 ± 0.0041 | 0.0170 ± 0.0012^†^
L. Epididymis | 0.0515 ± 0.0040 | 0.0480 ± 0.0023 | 0.0615 ± 0.0068 | 0.0549 ± 0.0040 | 0.0435 ± 0.0021
L. Testis | 0.1119 ± 0.0022 | 0.1119 ± 0.0016 | 0.1114 ± 0.0041 | 0.1085 ± 0.0038 | 0.1052 ± 0.0025
Spermatid measurements
Spermatid heads (10^6^/g testis) | 214.10 ± 17.77 | 233.47 ± 16.49 | 252.91 ± 18.67 | 254.21 ± 16.20 | 234.12 ± 21.35
Spermatid heads (10^6^/testis) | 23.93 ± 1.97 | 26.21 ± 2.10 | 27.93 ± 1.79 | 27.57 ± 2.00 | 24.80 ± 2.40
Epididymal spermatozoal measurements
Sperm motility (%) | 90.8 ± 2.2 | 94.7 ± 0.8 | 91.0 ± 3.6 | 92.4 ± 1.9 | 80.6 ± 7.4
Sperm (10^6^/g cauda epididymis) | 169.9 ± 21.6 | 151.1 ± 11.2 | 144.3 ± 8.9 | 153.9 ± 29.2 | 112.2 ± 22.4
Sperm (10^6^/cauda epididymis) | 3.4 ± 0.3 | 2.9 ± 0.2 | 3.2 ± 0.4 | 3.5 ± 0.7 | 1.8 ± 0.3^††^

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

** P ≤ 0.01.

^†^ Significantly different (P ≤ 0.05) from the untreated control group by Wilcoxon’s rank sum test.

^††^ Significantly different (P ≤ 0.01) from the untreated control group by a t-test (body weights) or Wilcoxon’s rank sum test (sperm/cauda epididymis).

^a^ Data are presented as mean ± standard error. Differences between the vehicle control group and the 25% and 50% groups are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements). Differences between the untreated control group and the 100% group are not significant by a t-test (tissue weights) or Wilcoxon’s rank sum test (spermatid measurements, sperm motility, and sperm/g cauda epididymis). Statistical comparisons between the two control groups are not presented.

Female mice administered 100% OTNE exhibited an increase in cycle length of approximately 1 day and displayed an increased probability of extended estrus as compared to the untreated controls (Table 9 and Table D-4). The increased probability of extended estrus was also observed in the 25% and 50% OTNE groups as compared to the vehicle controls. When displayed as days in any given stage and presented as a percentage, the 25%, 50%, and 100% OTNE groups exhibited more time in estrus than the respective control groups.

Table 9 Estrous Cycle Characterization for Female Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 25% | 50% | 100%
Number weighed at necropsy | 10 | 10 | 10 | 10 | 10
Necropsy body wt (g) | 28.5 ± 0.7 | 29.5 ± 0.7 | 28.9 ± 0.3 | 29.2 ± 0.4 | 29.4 ± 0.3
Proportion of regular cycling females^b^ | 9/10 | 10/10 | 10/10 | 10/10 | 9/10
Estrous cycle length (days) | 4.0 ± 0.2 | 4.5 ± 0.2 | 4.6 ± 0.2 | 4.5 ± 0.2 | 5.2 ± 0.3^††^
Estrous stages (% of cycle)
Diestrus | 38.8 | 38.8 | 31.3 | 33.8 | 37.5
Proestrus | 0.0 | 0.0 | 1.3 | 0.6 | 0.0
Estrus | 38.1 | 43.1 | 51.3 | 56.3 | 53.1
Metestrus | 15.0 | 11.9 | 10.0 | 6.3 | 6.9
Uncertain diagnosis | 8.1 | 6.3 | 6.3 | 3.1 | 2.5

^††^ Significantly different (P ≤ 0.01) from the untreated control group by Dunn’s test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences between the vehicle control group and the 25% and 50% groups are not significant by Dunnett’s test (body weights) or Dunn’s test (estrous cycle length). Differences between the untreated control group and the 100% group are not significant by a t-test (body weights). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the respective control group and each dosed group indicated the probability of extended estrus was significantly higher in the dose groups than the respective control groups. Statistical comparisons between the two control groups are not presented.

^b^ Number of females with a regular cycle/number of females cycling.

Compared to occurrences in the respective control groups, the incidences of several nonneoplastic lesions of the skin were significantly increased in dosed groups of males and females (Table 10, Table A-3, and Table A-4). At the site of application, the incidences of minimal to moderate hyperplasia and chronic active inflammation were significantly increased in all dosed groups of males and females. The incidences of minimal to mild hyperkeratosis were significantly increased in males administered 12.5% OTNE or greater and in all dosed groups of females. The incidences of fibrosis were significantly increased in all dosed groups of males except the 12.5% OTNE group, and in females administered 12.5% OTNE or greater. The incidences of epidermis suppurative inflammation were significantly increased in 100% OTNE males and in females administered 25% OTNE or greater. The incidences of hair follicle hyperplasia were significantly increased in 50% and 100% OTNE males and females administered 25% OTNE or greater.

Table 10 Incidences of Selected Nonneoplastic Lesions in Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Male
Skin, Site of Application^b^ | 10 | 10 | 10 | 10 | 10 | 9 | 10
Fibrosis^c^ | 0 | 0 | 4* (1.5)^d^ | 3 (2.0) | 8** (1.8) | 8** (1.6) | 10^††^ (2.0)
Hyperkeratosis | 0 | 0 | 2 (1.0) | 5* (1.4) | 5* (1.4) | 8** (1.4) | 10^††^ (1.7)
Hyperplasia | 0 | 0 | 9** (1.7) | 10** (1.9) | 9** (1.8) | 9** (2.3) | 10^††^ (2.8)
Inflammation, Chronic Active | 0 | 0 | 7** (1.4) | 10** (1.7) | 9** (1.7) | 9** (1.7) | 10^††^ (2.0)
Epidermis, Inflammation, Suppurative | 0 | 0 | 0 | 0 | 1 (1.0) | 1 (2.0) | 5^†^ (1.0)
Hair Follicle, Hyperplasia | 0 | 0 | 3 (1.0) | 2 (1.5) | 3 (2.3) | 7** (1.1) | 8^††^ (1.8)
Skin Adjacent to the Site of Application | 10 | 10 | 10 | 10 | 9 | 10 | 10
Fibrosis | 0 | 0 | 0 | 0 | 1 (1.0) | 2 (1.5) | 5^†^ (1.4)
Hyperkeratosis | 0 | 0 | 0 | 0 | 0 | 2 (2.0) | 5^†^ (1.6)
Hyperplasia | 0 | 0 | 0 | 2 (1.5) | 4* (1.0) | 3 (2.0) | 8^††^ (2.3)
Inflammation, Chronic Active | 0 | 0 | 0 | 2 (1.5) | 4* (1.3) | 2 (2.0) | 8^††^ (1.8)
Epidermis, Inflammation, Suppurative | 0 | 0 | 0 | 0 | 0 | 1 (2.0) | 4^†^ (1.0)
Hair Follicle, Hyperplasia | 0 | 0 | 0 | 1 (2.0) | 0 | 1 (2.0) | 5^†^ (1.6)
Liver | 10 | 10 | 10 | 10 | 9 | 10 | 10
Centrilobular, Hypertrophy | 0 | 1 (3.0) | 0 | 2 (1.0) | 3 (1.3) | 0 | 4^†^ (2.0)
Female
Skin, Site of Application | 10 | 10 | 10 | 10 | 10 | 6 | 10
Fibrosis | 0 | 0 | 2 (1.5) | 10** (1.6) | 10** (1.7) | 4** (1.3) | 9^††^ (2.0)
Hyperkeratosis | 0 | 0 | 5* (1.2) | 5* (1.2) | 10** (1.7) | 6** (1.8) | 10^††^ (2.1)
Hyperplasia | 0 | 0 | 10** (2.1) | 10** (1.8) | 10** (2.0) | 6** (2.3) | 10^††^ (2.8)
Inflammation, Chronic Active | 0 | 0 | 10** (1.8) | 10** (1.7) | 10** (2.0) | 6** (2.0) | 10^††^ (2.0)
Epidermis, Inflammation, Suppurative | 0 | 0 | 0 | 1 (1.0) | 4* (1.3) | 4** (1.3) | 7^††^ (1.3)
Hair Follicle, Hyperplasia | 0 | 0 | 3 (1.3) | 0 | 4* (2.8) | 3* (2.0) | 10^††^ (2.0)
Skin Adjacent to the Site of Application | 10 | 10 | 10 | 10 | 10 | 8 | 10
Fibrosis | 0 | 0 | 0 | 3 (1.3) | 0 | 0 | 6^††^ (1.5)
Hyperkeratosis | 0 | 0 | 0 | 1 (1.0) | 0 | 0 | 7^††^ (2.0)
Hyperplasia | 0 | 0 | 4* (1.0) | 3 (1.7) | 2 (1.0) | 3 (1.0) | 10^††^ (2.1)
Inflammation, Chronic Active | 0 | 0 | 4* (1.3) | 4* (1.5) | 2 (1.5) | 3 (1.3) | 8^††^ (1.9)
Epidermis, Inflammation, Suppurative | 0 | 0 | 0 | 0 | 0 | 0 | 8^††^ (1.6)
Hair Follicle, Hyperplasia | 0 | 0 | 0 | 0 | 1 (1.0) | 0 | 3 (2.0)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^†^ Significantly different (P ≤ 0.05) from the untreated control group by the Fisher exact test.

^††^ P ≤ 0.01.

^a^ Statistical comparisons between the two control groups are not presented.

^b^ Number of animals with tissue examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the skin adjacent to the site of application, the incidences of hyperplasia, hyperkeratosis, chronic active inflammation, fibrosis, and epidermis suppurative inflammation were significantly increased in 100% OTNE males and females, and the incidence of hair follicle hyperplasia was significantly increased in 100% OTNE males (Table 10, Table A-3, and Table A-4). The incidences of these lesions were also increased in most of the lower dosed groups of both sexes, sometimes significantly; these lesions were considered secondary to the spread of the test material from the site of application rather than a systemic effect. Lesions were not observed in examined control skin of male or female mice.

Compared to the vehicle controls (Figure 8 and Figure 9), hyperplasia and hyperkeratosis (Figure 10, Figure 11, and Figure 12) in the skin (site of application) were histologically similar to these lesions described in the rat; the same grading criteria were applied. Chronic active inflammation was characterized by increased numbers of scattered neutrophils, lymphocytes, and macrophages in the superficial dermis; increased numbers of mast cells and/or melanocytes were noted (Figure 11 and Figure 13). Fibrosis was characterized by replacement of the normally present dermal collagen fibers by discrete bands of pale basophilic fibrous connective tissue and/or increased numbers of fibroblasts (Figure 12 and Figure 13). Suppurative inflammation of the epidermis was characterized by discrete aggregates of degenerate neutrophils (pustules) within the stratum corneum and less frequently, hair follicles (Figure 12 and Figure 13). Hair follicle hyperplasia was characterized by increased numbers of follicle profiles and often the associated adnexal structures (e.g., sebaceous glands) within the dermis (Figure 10 to Figure 13).

Figure 8

Normal Epidermis (Arrows) in the Skin (Site of Application) of a Vehicle Control Female B6C3F1/N Mouse in the Three-month Dermal Study of OTNE (H&E)

Figure 9

Higher Magnification of Figure 8 (H&E)

Normal epidermis (arrows) consists of squamous epithelium (one to two layers thick) that is slightly keratinized.

Figure 10

Moderate Hyperplasia (Long Arrows) and Mild Hyperkeratosis (Short Arrows) in the Skin (Site of Application) of a Female B6C3F1/N Mouse Dermally Administered 6.25% OTNE for Three Months (H&E)

Compared to Figure 8, the epidermis and keratin layers are thickened. There are increased numbers of hair follicle profiles (hair follicle hyperplasia) within the dermis (curved arrows).

Figure 11

Higher Magnification of Figure 10 (H&E)

Compared to Figure 9, there is moderate thickening of the epidermal stratum granulosum (long arrows) and mild hyperkeratotic thickening of the keratin layer (short arrows). Note increased numbers of hair follicle profiles (hair follicle hyperplasia) and thickening of the follicular epithelium that is similar to that in the epidermis. There are increased infiltrates of inflammatory cells (chronic active inflammation) within the dermis. Note also that there is hyperplasia and hypertrophy of the sebaceous glands associated with the hyperplastic hair follicles (curved arrows).

Figure 12

Suppurative Inflammation in the Skin (Site of Application) of a Female B6C3F1/N Mouse Dermally Administered 100% OTNE for Three Months (H&E)

Suppurative inflammation (long arrows) consists of multifocal aggregates of neutrophils (pustules) within the stratum corneum. Compared to Figure 8, the dermis appears diffusely pale (short arrows) due to replacement of normally present dermal collagen fibers by connective tissue (fibrosis). Note also that there is epidermal hyperplasia and hyperkeratosis, and hair follicle hyperplasia.

Figure 13

Higher Magnification of Figure 12 (H&E)

Note multifocal aggregates of neutrophils (suppurative inflammation) within the stratum corneum and connective tissue (fibrosis) within the dermis (arrows). Note also epidermal hyperplasia and hyperkeratosis, hair follicle hyperplasia, and infiltrates of mononuclear inflammatory cells and neutrophils (chronic active inflammation) in the dermis extending into the subcutis.

In the liver, the incidence of centrilobular hypertrophy in 100% OTNE males was significantly greater than that in the untreated controls (Table 10 and Table A-3). There were no hepatic lesions in female mice. Centrilobular hypertrophy was of mild severity; affected hepatocytes were larger than the surrounding hepatocytes and had increased amounts of lightly eosinophilic to granular cytoplasm and loss of cytoplasmic glycogen.

## Genetic Toxicology

OTNE (Lot RAV0276433, the same lot used in the 3-month toxicity study with a concentration range of 100 to 10,000 µg/plate) was not mutagenic in Salmonella typhimurium strains TA98, TA100, or TA102, with or without exogenous metabolic activation (Table E-1). A second sample of OTNE (Lot RAV0276433 with a concentration range of 100 to 6,000 µg/plate) was also shown to be nonmutagenic in S. typhimurium strains TA98 or TA100, as well as in Escherichia coli strain WP2 uvrA/pKM101, with and without S9 activation (Table E-2).

The effect of 3 months of dermal exposure to OTNE on micronucleus frequency and erythropoiesis in F344/NTac rats and B6C3F1/N mice was examined in two experiments, a multidose experiment and a single-dose experiment. Four doses ranging from 6.25% to 50% OTNE were compared to a 95% ethanol vehicle control, whereas 100% (neat) OTNE was compared to an untreated control. No significant increases in micronucleated reticulocytes or erythrocytes were seen in male or female F344/NTac rats following exposure to OTNE, and no changes in the percentage of reticulocytes was observed in either sex of rat (Table E-3). In the multidose test in male rats, the mean frequency of micronucleated reticulocytes was significantly (P < 0.025) elevated over the control in the two highest dose groups, but the magnitudes of the increases were very small, the trend test was not significant, and the response measured in the group that received 100% OTNE was lower than either of these two values; therefore, the response in male rat reticulocytes in the multidose test was judged to be negative. In male mice, OTNE did not increase the frequency of micronucleated reticulocytes in the multi- or single-dose experiments (Table E-4). OTNE also did not increase the frequency of micronucleated mature erythrocytes in the multidose experiment. However, an increase in the frequency of micronucleated mature erythrocytes was detected in male mice exposed to 100% OTNE. Although this increase was statistically significant (P = 0.001), the magnitude of the increase was very small (1.45 ± 0.02 in the control versus 1.59 ± 0.03 in the treated group) and therefore, the result was judged to be equivocal. In female mice, OTNE did not increase the frequency of micronucleated reticulocytes in the multidose experiment. However, micronucleated reticulocytes were significantly increased (P = 0.005) in female mice exposed to 100% OTNE. Furthermore, micronucleated mature erythrocytes were significantly increased in a dose-dependent manner (P < 0.001) and also in the single-dose experiment (P < 0.001). Therefore, the results of these tests in female mice were judged to be positive. The percentage of reticulocytes was significantly increased in female mice exposed to 100% OTNE (1.08 ± 0.15 in the control versus 1.89 ± 0.25 in the treated group); however, the absolute percentage of reticulocytes in the 100% OTNE group was equal to or less than the percentages seen in the 12.5% to 50% OTNE-treated female mice, and other measures of reticulocyte numbers did not indicate that OTNE stimulated erythropoiesis. Considering all the data, the increase in the percentage of reticulocytes in the 100% OTNE group was not considered to be biologically significant.