# Materials and Methods

## Procurement and Characterization

### OTNE

OTNE (octahydro-tetramethyl-naphthalenyl-ethanone) was obtained as Iso-E Super^®^ from International Flavors and Fragrances, Inc. (Ringwood, NJ), in one lot (RAV0276433) that was used in the 3-month dermal studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Research Triangle Institute (Research Triangle Park, NC), and purity analyses were conducted by the study laboratory at BioReliance Corporation (Rockville, MD) (Appendix F). Reports on analyses performed in support of the OTNE studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a colorless to pale-yellow liquid, was identified as OTNE using infrared and proton nuclear magnetic resonance spectrometry and gas chromatography (GC) with mass spectrometry (MS) detection. All spectra were consistent with the structure of OTNE isomers. The purity of the test chemical was determined using GC with flame ionization detection (FID) and GC/MS. GC/FID analysis indicated four major peaks and nine minor peaks; each of the minor peaks was less than 1% of the total peak area. GC/MS analysis indicated mass spectra for the major peaks that were very similar, showing the same fragments with slight variations in relative abundance: These were tentatively identified as β-isomer, α-isomer, γ-isomer, and 1-(1,2,3,4,5,6,7,8-octahydro-2,3,5,5-tetramethyl-2-naphthalenyl)-ethanone based on the spectra and comparison to the literature.^36^ The overall purity of lot RAV0276433 was estimated to be greater than 96% relative to the four OTNE isomers: β-isomer (56.6%), α-isomer (18.0%), γ-isomer (17.7%), and 1-(1,2,3,4,5,6,7,8-octahydro-2,3,5,5-tetramethyl-2-naphthalenyl)-ethanone (3.9%). To ensure stability, the test chemical was stored in sealed amber glass vials at room temperature under a desiccant. Reanalysis of the test chemical was performed at the end of the study by the study laboratory using GC/FID; no degradation of the test chemical was detected.

### Ethanol

USP-grade 95% ethanol was obtained from Pharmco Products, Inc. (Brookfield, CT), in one lot (M0000) that was used as the vehicle in the 3-month dermal studies.

## Preparation and Analysis of Dose Formulations

Except for the 100% dose formulations, which were used neat, the dose formulations were prepared by mixing OTNE with 95% ethanol to give the required concentrations and stirring with a magnetic stir bar for at least 15 minutes. The dose formulations were stored in a flammable chemical storage cabinet in amber glass bottles sealed with Teflon^®^ silicone septa and an aluminum crimp seal under a nitrogen headspace at room temperature (~25°C). The dose formulations were prepared three times during the 3-month studies and analyzed for percent of target concentration (Table F-2). All 30 dose formulations analyzed for rats and mice were within 10% of the target concentrations. Animal room samples of these dose formulations were also analyzed; 28 of 30 for rats and 26 of 30 for mice were within 10% of the target concentrations.

## Animal Source

Male and female F344/NTac rats were obtained from the commercial colony at Taconic Farms, Inc. (Germantown, NY), and B6C3F1/N mice were obtained from the NTP colony at Taconic Farms, Inc. The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years, NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N rat exhibited sporadic seizures, idiopathic chylothorax, and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP to evaluate different rat models.^37^ The F344/NTac rat was used in four subchronic and two chronic studies between 2005 and 2006.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the BioReliance Corporation Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

On receipt, rats were 3 to 4 weeks old and mice were 4 to 5 weeks old. Animals were quarantined for 12 or 13 days (rats) or 14 or 15 days (mice); rats were 5 to 6 weeks old and mice were 6 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix H). All test results were negative.

Groups of 10 male and 10 female rats and mice received no treatment (untreated control) or dermal application of OTNE in 95% aqueous ethanol at concentrations of 0% (vehicle control), 6.25%, 12.5%, 25%, 50%, or 100% (neat) 5 days per week for 3 months (13 weeks). Groups of 10 male and 10 female special study rats received the same doses for 22 days. The study design included a second control group (untreated control) to allow for the appropriate comparison of the high dose group (100% OTNE) to a control group without aqueous ethanol. Formulations were administered at a volume of 0.5 mL/kg body weight (rats) or 2.0 mL/kg (mice). Thus, applied concentrations corresponded to 31.25 to 500 mg OTNE/kg body weight in rats and 125 to 2,000 mg/kg in mice. Doses were applied using a repeating pipette with a disposable tip to a consistent area that was shaved weekly. The shaved area was on the dorsal surface just posterior to the scapulae to the base of the tail and larger than the application site. The untreated control rats and mice were shaved similarly but received no liquid application, much like a sham control. Feed and water were available ad libitum. Rats and mice were housed individually. All animals were weighed, and clinical findings were recorded initially, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 2. Information on feed composition and contaminants is provided in Appendix G.

Table 2 Experimental Design and Materials and Methods in the Three-month Dermal Studies of OTNE

Three-month Study
Study Laboratory
BioReliance Corporation (Rockville, MD)
Strain and Species
F344/NTac rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 12 (males) or 13 (females) days Mice: 14 (males) or 15 (females) days
Average Age When Studies Began
Rats: 5 to 6 weeks Mice: 6 to 7 weeks
Date of First Dose
Rats: December 12 (males) or December 13 (females), 2006 Mice: December 14 (males) or December 15 (females), 2006
Duration of Dosing
3 months (13 weeks)
Date of Last Dose
Rats: March 12 (males) or March 13 (females), 2007 Mice: March 14 (males) or March 15 (females), 2007
Necropsy Dates
Rats: March 13 (males) or March 14 (females), 2007 Mice: March 15 (males) or March 16 (females), 2007
Average Age at Necropsy
Rats: 18 or 19 weeks Mice: 19 or 20 weeks
Size of Study Groups
10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly
Water
Tap water (Washington Suburban Sanitary Commission, Potomac Plant) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly
Bedding
Irradiated heat-treated, Sani-Chip hardwood bedding (P.J. Murphy Forest Products, Montville, NJ); changed weekly
Cage Filters
Omnishield paper, Remay 2024 (DuPont); changed every 2 weeks
Racks
Stainless steel (LabProducts, Inc., Seaford, DE); changed every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: ≥10/hour
Doses
Untreated control, 0% (vehicle control), 6.25%, 12.5%, 25%, 50%, or 100% (neat) OTNE
Type and Frequency of Observation
Observed twice daily; core study animals were weighed and clinical findings were recorded initially, on day 8, weekly thereafter, and at the end of the studies.
Method of Euthanasia
Carbon dioxide asphyxiation
Necropsy
Necropsies were performed on all core study rats and mice. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
Blood was collected from the retroorbital plexus of special study rats on days 3 and 23 and from core study rats at the end of the study for hematology and clinical chemistry. Blood was collected from the retroorbital sinus of core study mice at the end of the study for hematology. Hematology: hematocrit (automated and manual); hemoglobin; erythrocyte, reticulocyte, and platelet counts; erythrocyte distribution of width; mean platelet volume; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical Chemistry: urea nitrogen, creatinine, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids
Histopathology
Complete histopathology was performed on core study rats and mice in the untreated control, vehicle control, and 100% OTNE groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone (femur) with marrow, brain, clitoral gland, esophagus, eye, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung (with mainstem bronchus), lymph nodes (mandibular and mesenteric), mammary gland, nose, oral cavity and larynx, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin (site of application and control sites), spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, tongue, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology
At the end of the studies, sperm samples were collected from male rats and mice in the untreated control, vehicle control, 25%, 50%, and 100% OTNE groups for sperm motility evaluations. The following parameters were evaluated: spermatid heads per gram testis and per testis, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 16 consecutive days prior to the end of the studies from female rats and mice in the untreated control, vehicle control, 25%, 50%, and 100% OTNE groups for vaginal cytology evaluations.
Liver Cytochrome P450 Activity
Liver samples were collected from five male and five female special study rats per dose group on day 23 and from five male and five female core study rats and mice per dose group at the end of the studies. Livers were analyzed for total microsomal protein content and Cyp2e1 activity.

On days 3 and 23, blood was collected from the retroorbital plexus of special study rats for hematology and clinical chemistry analyses only (no additional evaluations in mice). Blood was collected from the retroorbital plexus and sinus of core study rats and mice, respectively, at the end of the 3-month studies for hematology and clinical chemistry (rats) analyses. Blood for hematology analyses was placed in tubes containing EDTA as the anticoagulant. Hematology parameters were determined using an ABX Pentra 60 C+ analyzer (HORIBA Instruments, Inc., Irvine, CA). For clinical chemistry analyses, blood samples were placed in serum separator tubes and centrifuged, and the serum was analyzed using a Hitachi 717 chemistry analyzer (Boehringer Mannheim, Indianapolis, IN) and commercially available reagents. The parameters measured are listed in Table 2.

The vehicle, ethanol, is metabolized by cytochrome P4502E1 (Cyp2e1) to form reactive products that are associated with hepatic injury.^38^ In order to distinguish potential OTNE-related effects on the liver from ethanol-induced liver changes, Cyp2e1 activity was also measured in control and dosed groups. At the scheduled euthanasia of special study rats on day 23, consistent portions of the median and left lateral liver lobes not scheduled for histologic evaluation were excised from the first five male and female rats per dose group encountered during the random order for bleeds. Comparable sections of the livers were excised from the first five male and female core study rats scheduled for necropsy at the end of the study. For mice, the entire portion of the liver not used for histologic evaluation was excised from the first five male and female mice per dose group necropsied at the end of the study. The liver portions were immediately flash frozen at −60°C or less. The rat and mouse liver samples were shipped on dry ice to In Vitro Technologies (IVT, Baltimore, MD). Upon arrival, liver samples were stored at −70° ± 10°C until processed into microsomes. IVT prepared microsomes from the livers by differential centrifugation and analyzed the liver samples for total protein by the bicinchoninic acid (BCA) method using the BCA Protein Assay Kit (Pierce Chemical Co., Rockford, Il). Cyp2e1 activity was measured by monitoring lauric acid 11-hydroxylase activity. Microsomes were incubated with [^14^C]lauric acid and a NADPH-regenerating system, and the rate of formation of 11-hydroxylauric acid was analyzed using a radiometric high performance liquid chromatography (HPLC) method. Two replicates of each liver sample were analyzed for all dosed and control groups.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on core study rats and mice in the untreated control, vehicle control, 25%, 50%, and 100% OTNE groups. The parameters evaluated are listed in Table 2. For 16 consecutive days prior to scheduled terminal euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on rats and mice in the untreated control, vehicle control, and 100% OTNE groups. The skin at the site of application, skin adjacent to the site of application, and control skin were examined in all groups of rats and mice, and the liver was examined in all groups of rats and mice. Table 2 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^39^ and Boorman et al.^40^

## Statistical Methods

For all statistical comparisons, the data from the 100% OTNE groups were compared to the untreated control groups. Data from OTNE-treated groups (6.25% to 50%) were compared to the vehicle controls. With the exception of micronucleus data presented in Appendix E, statistical comparisons between the vehicle control and untreated control groups are not presented in this Toxicity Study Report. In general, there were no statistically significant differences between control groups except in two instances. First, Cyp2e1 activity was decreased 36% in female rats from the vehicle control group compared to the untreated control group. Second, the mean final body weights of male mice were 7% lower in the vehicle controls compared to the untreated controls. The biological significance of these two discrepancies was considered negligible.

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^41^ a procedure based on the overall proportion of affected animals, was used to determine significance between dosed and vehicle control groups and between the 100% OTNE and untreated control groups.

### Analysis of Continuous Variables

For dosed groups compared to the vehicle control groups, two approaches were employed to assess the significance of pairwise comparisons in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^42^ and Williams.^43,44^ Hematology, clinical chemistry, total microsomal protein, cytochrome P450 activity, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^45^ (as modified by Williams^46^) and Dunn.^47^ Jonckheere’s test^48^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^49^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the vehicle control group using the Fisher exact test.^41^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^50^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

For comparison of the 100% (neat) group to the untreated control group, a t-test was used to determine significant differences in organ and body weight data, and Wilcoxon’s^51^ rank sum test was used for hematology, clinical chemistry, total microsomal protein, cytochrome P450 activity, spermatid, and epidymal spermatozoal data. Female reproductive parameters were analyzed as described for the comparison of the dosed groups to the vehicle control groups.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^52^ In addition, as records from the 3-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, and final pathology tables. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicology

### Bacterial Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al.^53^ in the first study, and in the second study, a slightly modified protocol was used, as described below. Both studies used the same lot (RAV0276433) of OTNE that was used in the 3-month studies. OTNE was sent to the testing laboratory as a coded sample. In the first study, it was incubated with the Salmonella typhimurium tester strains (TA98, TA100, or TA102) either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rats) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

In the second study, following incubation of the bacteria with OTNE for 20 minutes at 37°C, top agar supplemented with either L-histidine (for the Salmonella strains) or L-tryptophan (for the E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

In both studies, each trial consisted of triplicate plates of concurrent positive and negative controls and of at least five doses of OTNE. In the absence of toxicity, the high dose was limited by experimental design in the first study to 10,000 µg/plate and in the second to 6,000 µg/plate.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold-increase required for a chemical to be judged positive or weakly positive.

### In Vivo Peripheral Blood Micronucleus Test Protocol in Rats and Mice

The procedures used for the mouse and rat peripheral blood micronucleus assay have been described in detail.^54-56^ Briefly, at the termination of the 3-month toxicity studies with OTNE, one to two drops of blood from male and female F344/NTac rats and male and female B6C3F1/N mice were collected in microtubes with EDTA and shipped on cool packs to the genetic toxicity testing laboratory for processing and fixation in ultracold methanol, as per procedures described in the MicroFlow^BASIC^ Kit for rat blood samples or mouse blood samples (Litron Laboratories, Rochester, NY). A FACSCalibur flow cytometer (Becton Dickinson, San Jose, CA) was used to carry out the analyses of the samples. Reticulocytes were identified by the presence of an active transferrin receptor (CD71^+^) on the cell surface and mature erythrocytes were CD71-negative. For the rat samples, only reticulocytes with the highest CD71 activity were evaluated due to the speed and efficiency with which the rat spleen removes damaged reticulocytes from circulation. Thus, although micronucleus frequency was evaluated in both reticulocytes and erythrocytes, the appropriate cell population for this assessment in rats is the young reticulocyte population. Micronuclei were detected using propidium iodide (a DNA stain) in conjunction with RNase treatment. Approximately 1 × 10^6^ erythrocytes (CD71^−^), and 20,000 reticulocytes (CD71^+^) were evaluated per animal for presence of micronuclei (propidium iodide-associated fluorescence). In addition, for each blood sample, the percentage of reticulocytes in 1 × 10^6^ erythrocytes was determined as a measure of OTNE-associated bone marrow toxicity.

Approximately 1 × 10^6^ erythrocytes and 20,000 reticulocytes were scored per mouse for presence of micronuclei. Based on prior experience with the large number of cells scored using flow cytometric scoring techniques,^57^ it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose and Williams’ test is used to test for pairwise differences between each treatment group and the control group. In the case of unequal variances, Jonckheere’s test is used to test for linear trend and Dunn’s test is used for pairwise comparisons of each treatment group with the control group. To correct for multiple pairwise comparisons, the P value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is greater than 1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the controls are considered statistically significant at P = 0.025. In the micronucleus assay, a positive response is preferably based on the observation of both a significant trend as well as an observation of at least one dose group significantly elevated over the concurrent control group. If only one statistical test (trend or pairwise) is significant, the micronucleus assay is judged to be equivocal. The absence of both a significant trend and a significant dose results in a negative call for the assay. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

## Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The Abstract of this Toxicity Study Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.