# Introduction

Figure 1

Octahydro-tetramethyl-naphthalenyl-ethanone (OTNE) (CASRN 54464-57-2 (β-isomer), 68155-67-9 (α-isomer), 68155-66-8 (γ-isomer); Chemical Formula: C_16_H_26_O; Molecular Weight: 234.38)

Synonyms: 1´,2´,3´,4´,5´,6´,7´,8´-Octahydro-2´,3´,8´,8´-tetramethyl-2´-acetonaphthone; 1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-acetonaphthone; 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthalenyl)ethanone; 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one; 1-(1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthyl)ethan-1-one; 1-(1,2,3,4,5,6,7,8-octahydro-2,3,5,5-tetramethyl-2-naphthyl)ethan-1-one.

Trade Names: Amberonne, Ambralux, Boisvelone, Iso Ambois Super, Iso E Super^®^, Isocyclemone, Isocyclemone E, Orbitone

Octahydro-tetramethyl-naphthalenyl-ethanone (OTNE) is a fragrance ingredient with an unsaturated alkyl cyclic ketone structure that is formed as a mixture of isomers.^1^ The main isomer is identified as 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthalenyl)ethanone and is referred to as the β-isomer.^2^ Two other predominant isomers within the mixture are 1-(1,2,3,4,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthalenyl)ethanone (α-isomer) and 1-(1,2,3,5,6,7,8,8a-octahydro-2,3,8,8-tetramethyl-2-naphthalenyl)ethanone (γ-isomer). A typical composition of the mixture consists of 30% to 65% by weight of the β-isomer (CASRN 54464-57-2), 10% to 26% α-isomer (CASRN 68155-67-9), and 8% to 20% γ-isomer (CASRN 68155-66-8). Minor OTNE isomers also have been identified in mixtures.^3^ OTNE is commonly referred to by the commercial name Iso E Super^®^, which is the most prevalent name encountered in the literature.

## Chemical and Physical Properties

The OTNE mixture is in liquid form with a pale-yellow color and an amber or woody odor. Some of the measured or calculated properties of the three primary isomers are listed in Table 1.

Table 1 Physical Properties of Primary OTNE Isomers

| β-Isomer | α-Isomer | γ-Isomer
Boiling Point (°C) | 110–117 @ 1.0–1.5 Torr 124–135 @ 2.1–2.9 Torr 312.2 ± 31.0 @ 760 Torr^a^ | 311.4 ± 31.0 @ 760 Torr^a^ | 311.4 ± 31.0 @ 760 Torr^a^
Vapor Pressure (Torr) | 5.38 × 10^-4a^ | 5.65 × 10^-4a^ | 5.65 × 10^-4a^
Specific Gravity | 0.96–0.97 @ 20°C^b^ | Not located | Not located
Water Solubility | 1.077 mg/L @ 25°C^b^ | 2.725 mg/L @ 25°C^c^ | 2.725 mg/L @ 25°C^c^
Bioconcentration Factor | 3,720.25 @ pH 1–10, 25°C^a^ | 4,449.43 @ pH 1–10, 25°C^a^ | 4,613.20 @ pH 1–10, 25°C^a^

^a^ Calculated properties using Advanced Chemistry Development (ACD/Labs) Software V11.02 (©1994-2013 ACD/Labs).

^b^ Scognamiglio et al.^4^

^c^ Belsito et al.^1^

## Production, Use, and Human Exposure

OTNE is produced commercially by Diels-Alder condensation of β-myrcene with 3-methyl-3-pentene-2-one in the presence of aluminum chloride to give a monocyclic intermediate that is cyclized in the presence of 85% phosphoric acid.^5^ OTNE is manufactured in a semicontinuous process with minimal potential for occupational exposure. The annual volumes of OTNE produced in North America for 2000, 2004, 2008, and 2011 were 700, 1,300, 2,100, and 2,800 tons/year, respectively.^3^ The total reported production volume for each of the predominant OTNE isomers (α, β, and γ) as reported in the nonconfidential 2006 Inventory Update Rule (IUR), range from 1,000,000 to less than 10,000,000 pounds per year. In 2012, the production volume of the β-isomer was 1,000,000 to 10,000,000 pounds per year in the Chemical Data Reporting database.^6-8^

A search found more than 30 products containing OTNE for use as a perfume ingredient in soap, shampoo, cologne, liquid detergent compounds, and malodor-reducing compounds, such as fabric freshening compounds, antiperspirants or deodorants, and air freshening compounds. Typical OTNE concentrations are less than 1% in household products, and fine fragrance ingredients may contain up to 20% OTNE.^3,4^

For the general population, exposure to OTNE is via inhalation and the skin through the use of products (e.g., fragrances and perfumed personal care products) containing the ingredient. Additional exposures may result from ingestion of water or food containing the ingredient as a contaminant. In one human study, OTNE was detected in 34% of breast milk samples (37/110 samples) above the method detection limit, but the levels were below the method quantification limit of 1.5 ng/g lipid.^9^ Human dermal systemic exposure to OTNE (β-isomer) was calculated to be 0.4604 mg/kg per day based upon the concentrations in 10 personal care and cosmetic products, the amount of the product applied, the number of applications per day of each product, and the length of time the product was present on the skin.^4^

Detection of OTNE in the environment (e.g., sludge, wastewater, river water, and house dust samples) provides documentation for its use as well as exposure scenarios to humans and aquatic life. OTNE was detected in the majority of house dust samples obtained from Canadian homes. OTNE was detected in 82% of the samples collected from the vacuum systems used by the participants, and concentrations ranged from not detected to 5,620 ng/g with a median concentration of 212 ng/g. In fresh house dust samples, the detection frequency was 94%. The concentration range and median concentrations extended from not detected to 125,000 ng/g and 252 ng/g, respectively^10^ (Note: the study references the trade name Iso E Super^®^ and the β-isomer CASRN). OTNE was also detected in municipal wastewater and in effluents from water treatment facilities within the United States and Germany.^11,12^ In United States facilities with activated sludge or trickling filter wastewater treatment, OTNE influent concentrations were 3.470 and 3.250 µg/L, respectively, and final effluent concentrations were 0.110 and 0.334 µg/L, respectively. Thus, a 96.8% removal rate was achieved via activated sludge wastewater treatment versus 89.7% removal following trickling filter wastewater treatment^13^ (Note: studies reference, either through CASRN or structure, the β-isomer). Furthermore, studies have indicated that OTNE is degraded in environmental samples. In a river water test, degradation half-lives of 5 days or less were reported. In soil core and leachate samples, OTNE levels decreased by 60% after 3 months and were not detected within 1 year. The maximum measured bioaccumulation factor was noted to be 850 in bluegill fish. Evaluated metabolites of OTNE were more polar than the parent, suggesting that they were not likely to accumulate.^3^

## Regulatory Status

In the United States, OTNE is listed in the Toxic Substances Control Act (TSCA) Inventory under the 9CI name ethanone, 1-(1,2,3,4,5,6,7,8-octahydro-2,3,8,8-tetramethyl-2-naphthalenyl); this is specific to the β-isomer. In 2012, the USEPA added four of the OTNE isomers (CASRNs: 54464-57-2; 54464-59-2; 68155-66-8; 68155-67-9) to the TSCA Work Plan for Chemical Assessments.^14^ As of 2014, the isomers are still listed in the TSCA Work Plan Update for their evaluation regarding environmental persistence and occurrence.^15^

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

### Experimental Animals

There are limited data on the absorption, distribution, metabolism, excretion, and toxicokinetics of OTNE in experimental animals, although OTNE disposition can be inferred from data summaries submitted to the Registration, Evaluation, Authorisation, and Restriction of Chemicals (REACH) Dossiers available in the European Chemicals Agency (ECHA) database as well as in a published summary of industry studies.^4^ In one such report, maternal transfer was assessed in pregnant Sprague Dawley rats by gavage administration of 2 or 20 mg [^14^C]OTNE/kg body weight in corn oil from gestation day 14 to postnatal day 7.^16^ Milk and blood samples were collected from dams on postnatal days 3 and 7 at 4, 8, and 24 hours following dose administration. Total radioactivity levels in plasma and milk decreased with time, and unmetabolized OTNE was not detected in the milk. Low levels of radioactivity were detected by whole-body radiography in the placenta and fetus following exposure of pregnant Sprague Dawley rats from gestation days 14 to 19 to 2 mg [^14^C]OTNE/kg body weight, suggesting minimal maternal transfer of OTNE. Radioactivity also was present in the small intestine contents, preputial gland, stomach, liver, large intestine contents, thyroid gland, and bladder of the dams.

The disposition of OTNE in male F344 rats after gavage or dermal exposure was studied by NTP using [^14^C]OTNE (β-isomer).^17^ β-OTNE was well absorbed following gavage administration of 20 mg/kg, and the majority of the administered dose was excreted in urine (28%) and feces (39%) by 48 hours. Approximately 73% of the 20 mg/kg dose was eliminated in bile in 48 hours confirming that the fecal excretion was not due to poor absorption but biliary excretion. Additionally, approximately 80% of the dose in the bile was excreted within the first 4 hours, while the fecal excretion continued through 48 hours suggesting enterohepatic recirculation of OTNE. Radioactivity in tissues reached maximal levels between 4 and 8 hours, and the highest levels of radioactivity were found in the liver, kidney, pancreas, and adipose. The estimated elimination half-lives, based on the total radioactivity, were greater than or equal to 20 hours in blood and most tissues examined. Profiling of urine showed the presence of at least nine metabolites, although the identities of the metabolites were not determined.

Disposition was also examined by NTP in male F344 rats following a single dermal application of 55 or 550 mg/kg [^14^C]β-OTNE in ethanol to covered and uncovered dose sites after 24, 48, or 96 hours.^17^ For comparison with the 3-month dermal studies in rats, the corresponding formulation concentrations were 0.55% and 5.5% OTNE. There was a general trend that the percent dose absorbed increased and the percent dose at dose-site skin decreased with time in both covered and uncovered groups. When the dose site was covered, approximately 14% of the applied dose was absorbed by 96 hours in both 55 and 550 mg/kg groups. When the dose site was uncovered, the total dose absorbed 96 hours postdosing was 33% and 72%, for 55 and 550 mg/kg, respectively, suggesting significant absorption due to oral grooming. Similar to gavage administration, the primary routes of excretion were through feces (4.0% to 12.3%) and urine (5.1% to 13.7%) at 96 hours in covered and uncovered animals, respectively. The highest levels of radioactivity were found in the liver, kidney, adipose, and pancreas. Blood elimination half-lives estimated for 55 and 550 mg/kg uncovered dose groups were 70 and 40 hours, respectively; half-lives for covered dose groups were not reported due to the lack of sufficient data points to define the blood concentration versus time profiles.

### Humans

Human summary data regarding the absorption of OTNE have been submitted to REACH and are available in the ECHA database. In this in vitro absorption study, 1% [^14^C]OTNE (w/v) in ethanol was applied to human epidermis.^18^ Permeation was measured from 2 through 48 hours, and results indicated that approximately 29% of the applied dose was absorbed. The rate of permeation was linear with no plateau noted.

## Toxicity

### Experimental Animals

The reported oral and dermal acute toxicity values (LD_50_) were greater than 5,000 mg/kg in male and female TacN(SD)fBR and Sprague Dawley rats.^4,19,20^

In a 28-day subchronic study in male and female Sprague Dawley rats, OTNE was administered orally at 50, 150, or 1,000 mg/kg in corn oil. A subset of animals was kept in housing an additional 14 days to assess recovery. The study summary, available in the ECHA database and summarized by Scognamiglio et al.,^4^ indicated that no treatment-related deaths occurred, but poor grooming, decreased body weights, and increased water consumption were observed during treatment in the high dose males and females. All effects were reversed during the 14-day recovery period. Treatment-related effects were reported in high dose animals (e.g., increased cholesterol levels in males and females as well as decreased glutamic pyruvic transaminase levels in males). Increased liver weights and centrilobular hepatocyte enlargement were observed in high dose males and females. Eosinophilic inclusions in the cortical tubules were noted in mid- and high-dose males; some recovery was observed in high dose males. The report summary concluded that the no-observed-adverse-effect level (NOAEL) and no-observed-effect level (NOEL) for OTNE when administered orally for at least 4 weeks are 1,000 and 15 mg/kg body weight per day, respectively.^4,21^

Contact sensitization and irritancy following dermal exposure to OTNE in an acetone:olive oil (4:1) vehicle was evaluated in female BALB/c mice by NTP.^22^ To reduce the number of animals needed for the studies, the local lymph node assay (LLNA) and irritancy assay were combined. All mice treated with OTNE (0.5%, 1%, 2.5%, 5%, 25%, or 50% applied to the dorsum of the ear) demonstrated significant irritation at the site of application, as measured by swelling of the ear pinna 24 hours after the last exposure. In the LLNA, significant increases in lymph node cell proliferation were observed in the 25% and 50% groups only (172% and 467%, respectively, as compared to vehicle controls). The maximum stimulation index (SI) for these studies was 5.68 in the 50% OTNE group. The SI is the ratio of lymph node cell proliferation in the OTNE test group to that of the matched vehicle control group. A substance is considered a dermal sensitizer if at least one concentration of the test article results in a mean SI of 3 or more, although statistically significant changes in disintegrations per minute below the SI = 3 threshold are also considered. To further investigate the sensitization potential of OTNE, the Mouse Ear Swelling Test was performed. In the sensitization phase, three concentrations of OTNE (0.5%, 5%, and 50%) were used, and 50% OTNE was applied during the challenge phase. OTNE did not significantly increase mouse ear thickness at either 24 or 48 hours postchallenge at any of the concentrations evaluated. These results suggest that, under the experimental conditions utilized in this study in female BALB/c mice, the positive response in the LLNA was likely due to the irritant effects of OTNE.

OTNE-induced skin hypersensitivity was examined in multiple LLNA studies with female CBA/J mice. The results are reported by the European Chemicals Agency and classify OTNE as a skin sensitizer following application of 2.5%, 5%, 10%, 25%, or 50% OTNE (v/v) in 3:1 diethyl phthalate:ethanol.^23-25^ The SI values for these studies ranged from 11.3 to 34.2 when 50% OTNE was applied. The full study reports for these investigations were not available (Robust Summary Data from REACH Dossiers in the ECHA database) so it is not clear whether the doses used in these LLNA studies were nonirritating or whether the differences in the results were due to the animal strains or vehicles used.

### Humans

The majority of OTNE-related toxicity studies in humans have been to examine whether its dermal application can cause skin irritation or sensitization. When OTNE was applied in a patch test, two cases (out of 1,069 patients) of an allergic reaction were observed on day 3 or 4 of application.^26^ More recently, 0.2% of tested individuals (1,855 patients) were identified as sensitive to OTNE^27^ (Note: the study references the trade name Iso E Super^®^ and CASRN 54464-57-2). In another evaluation, OTNE sensitization was reported in 1.7% of fragrance-sensitive individuals (178 volunteer patients) subjected to a patch test.^28^

The European Chemicals Agency has reported the results of several human patch test studies, which are also summarized by Scognamiglio et al.^4^ and Belsito et al.^1^ In one study, OTNE irritation potential was examined with 20%, 40%, 60%, or 75% test article applied two times over a 96-hour period in 23 subjects.^29^ At 20% OTNE, minimal erythema was reported in select individuals, however, dermal irritation was negligible in 40% to 75% OTNE-treated subjects. In a different repeated patch test study conducted on 101 individuals, the potential for OTNE to induce contact sensitization was examined.^30^ OTNE was applied via an occluded patch, and applications were repeated three times per week for 3 weeks. Ten to 17 days after the last application, a challenge patch was applied and the response was evaluated 24, 48, and 72 hours later. Slight to mild transient erythema was observed in 17 individuals during the 3-week induction phase. During the challenge phase, four individuals experienced slight or mild erythema at the later time points.

In vitro studies using reconstructed human epidermis classified OTNE as an irritant to the skin.^31^

## Reproductive and Developmental Toxicity

### Experimental Animals

There are no data on the reproductive toxicity of OTNE in the literature and limited data on developmental toxicity of OTNE in experimental animals.^2,32^ In a preliminary study, pregnant Sprague Dawley rats were orally gavaged with 240, 480, 960, or 1,920 mg/kg OTNE (neat material) or water (control) from gestation days 7 to 17. Rats were euthanized on gestation day 21, and one rat was euthanized moribund on gestation day 16. Clinical signs in all treated animals included chromorhinorrhea, excessive salivation, and the presence of a red perioral substance. Urine stained abdominal fur was noted in the two highest dose groups, and amber colored urine was observed in the highest dose group. No statistically significant effects were noted in litter parameters.

Following the preliminary study, pregnant Sprague Dawley rats were orally gavaged with 96, 240, or 480 mg/kg body weight per day from gestation days 7 to 17.^2^ Rats were euthanized on gestation day 21. No treatment-related deaths were reported. Clinical signs attributed to treatment included increased salivation at all doses and an increased incidence of urine-stained abdominal fur in high dose animals. Body weight gain was lower at all dose levels from gestation days 7 to 10. Additionally, high dose dams exhibited lower body weight gain from gestation days 11 to 21. Feed consumption was lower in all dosed groups. No treatment-related effects were observed on uterine parameters (e.g., implantations); gross external, soft tissue, or skeletal malformations; or number of ossification sites/fetus per litter. The maternal and developmental NOAEL was reported as 240 mg/kg per day.

### Humans

No studies were found in the literature on the reproductive or developmental toxicity of OTNE in humans.

## Carcinogenicity

No carcinogenicity studies of OTNE in experimental animals or epidemiology studies in humans have been reported in the literature.

## Genetic Toxicity

No studies were found in the open literature on the genotoxicity of OTNE. However, little genotoxic potential for OTNE can be inferred from data submitted to REACH and available in the ECHA database. In these industry-sponsored studies, OTNE (dissolved in DMSO) was reported to be negative in bacterial mutagenicity tests that employed Salmonella typhimurium strains TA98, TA100, TA1535, TA1537, or TA1538 or Escherichia coli strain WP2 uvrA. OTNE concentrations ranged from 312.5 to 5,000 µg/plate, with or without induced rat liver S9 activation enzymes,^33^ and no cytotoxicity was reported at any of the tested concentrations. In mammalian cells, no mutagenicity was observed in mouse lymphoma L5178Y tk^+/-^ cells treated with OTNE (dissolved in ethanol) at concentrations up to 90 µg/mL in the presence of S9 and at concentrations up to 40 µg/mL without S9.^34^ The effect of OTNE (dissolved in DMSO) on chromosomal aberrations was assessed in human lymphocytes with standard and extended incubation times.^35^ OTNE was considered to be negative for inducing chromosomal aberrations when tested at concentrations up to 125 µg/mL in the presence of S9 and at concentrations up to 50 µg/mL without S9.^34^ Although these test results are freely available in the ECHA database and are summarized in Scognamiglio et al.,^4^ lack of access to the original studies precludes independent assessment of the data or the protocols under which they were generated.

## Study Rationale

The fragrance ingredient OTNE was nominated by a private individual for toxicology testing based on its widespread use as a constituent of a fragrance mixture and the lack of toxicity data via a relevant route of exposure. In response, NTP conducted 3-month toxicity studies of OTNE administered by dermal application to male and female F344/NTac rats and B6C3F1/N mice.