# Appendix F Chemical Characterization and Dose Formulation Studies

## F.1 Procurement and Characterization

### F.1.1 OTNE

OTNE (octahydro-tetramethyl-naphthalenyl-ethanone) was obtained as Iso-E Super^®^ from International Flavors and Fragrances, Inc. (Ringwood, NJ), in one lot (RAV0276433) that was used in the 3-month dermal studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Research Triangle Institute (Research Triangle Park, NC), and purity analyses were conducted by the study laboratory at BioReliance Corporation (Rockville, MD). Reports on analyses performed in support of the OTNE studies are on file at the National Institute of Environmental Health Sciences.

The test article, a colorless to pale-yellow liquid, was identified as OTNE by the analytical chemistry laboratory using infrared (IR) and proton nuclear magnetic resonance (NMR) spectrometry and gas chromatography (GC) with mass spectrometry (MS) detection. All spectra were consistent with the structure of OTNE isomers. Representative IR and NMR spectra are presented in Figure F-1 and Figure F-2, respectively.

The purity of the test chemical was determined by the analytical chemistry laboratory using GC with flame ionization detection (FID) and GC/MS. The GC systems included a gas chromatagraph (Hewlett-Packard, Palo Alto, CA), an Equity^®^-5, 30 m × 0.32 mm, 0.25 µm film (Supelco, Inc., Bellefonte, PA) column, an oven temperature program of 60°C for 20 minutes, then 10°C/minute to 200°C, held for 26 minutes, helium carrier gas at a flow rate of 1 or 2 mL/minute, with flame ionization or mass spectrometry (Agilent Technologies, Santa Clara, CA) detection.

GC/FID analysis indicated four major peaks and nine minor peaks; each of the minor peaks was less than 1% of the total peak area. GC/MS analysis indicated mass spectra for the major peaks that were very similar, showing the same fragments with slight variations in relative abundance: These were tentatively identified as β-isomer, α-isomer, γ-isomer, and 1-(1,2,3,4,5,6,7,8-octahydro-2,3,5,5-tetramethyl-2-naphthalenyl)ethanone based on the spectra and comparison to the literature.^36^ The overall purity of lot RAV0276433 was estimated to be greater than 96% relative to the four OTNE isomers: β-isomer (56.6%), α-isomer (18.0%), γ-isomer (17.7%), and 1-(1,2,3,4,5,6,7,8-octahydro-2,3,5,5-tetramethyl-2-naphthalenyl)ethenone (3.9%).

To ensure stability, the test chemical was stored in sealed amber glass vials at room temperature under a desiccant. Reanalysis of the test chemical was performed at the end of the study by the study laboratory using GC/FID by a method similar to that described previously; no degradation of the test chemical was detected.

### F.1.2 Ethanol

USP-grade 95% ethanol was obtained from Pharmco Products, Inc. (Brookfield, CT), in one lot (M0000) that was used as the vehicle in the 3-month dermal studies.

## F.2 Preparation and Analysis of Dose Formulations

Except for the 100% dose formulations, which were used neat, the dose formulations were prepared by mixing OTNE with 95% ethanol to give the required concentrations and stirring with a magnetic stir bar for at least 15 minutes (Table F-1). The dose formulations were stored in a flammable chemical storage cabinet in amber glass bottles sealed with Teflon^®^ silicone septa and an aluminum crimp seal under a nitrogen headspace at room temperature (~25°C). The dose formulations were prepared three times during the 3-month studies.

Stability studies of 12.5% in 95% ethanol formulations made with lot RAV0276433 were performed by the analytical chemistry laboratory using GC/FID by a method similar to that described previously. Stability was confirmed for at least 42 days at ambient temperatures and for at least 3 hours under simulated animal room conditions.

The dose formulations were analyzed three times by the study laboratory using GC/FID by a system similar to that previously described. All 30 of the dose formulations analyzed for rats and mice were within 10% of the target concentrations (Table F-2). Animal room samples of these dose formulations were also analyzed; 28 of 30 for rats and 26 of 30 for mice were within 10% of the target concentrations.

Table F-1 Preparation and Storage of Dose Formulations in the Three-month Dermal Studies of OTNE

Three-month Dermal Study
Preparation
Except for the 100% (neat) dose, the dose formulations were prepared by mixing OTNE with 95% ethanol to give the required concentrations and stirred with a magnetic stir bar for at least 15 minutes. The dose formulations were prepared three times during the 3-month studies.
Chemical Lot Number
RAV0276433
Maximum Storage Time
42 days
Storage Conditions
The dose formulations were stored in a flammable storage cabinet in amber glass bottles sealed with Teflon^®^ silicone septa and an aluminum crimp seal under a nitrogen headspace at room temperature (~25°C).
Study Laboratory
BioReliance Corporation (Rockville, MD)

Table F-2 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Dermal Studies of OTNE

Date Prepared | Date Analyzed | Target Concentration (% v/v) | Determined Concentrationa (% v/v) | Difference from Target (%)
December 5, 2006 | December 6, 2006 | 6.25 | 6.48 | +4
| | 6.25 | 6.56 | +5
| | 12.5 | 12.2 | −2
| | 12.5 | 12.6 | +1
| | 25 | 25.5 | +2
| | 25 | 24.8 | −1
| | 50 | 48.8 | −2
| | 50 | 52.0 | +4
| | 100 | 102 | +2
| | 100 | 104 | +4
| January 21, 2007^b^ | 6.25 | 6.13 | −2
| | 6.25 | 6.27 | 0
| | 12.5 | 12.4 | −1
| | 12.5 | 12.1 | −3
| | 25 | 24.7 | −1
| | 25 | 24.8 | −1
| | 50 | 49.7 | −1
| | 50 | 49.0 | −2
| | 100 | 104 | +4
| | 100 | 102 | +2
| January 29, 2007^c^ | 6.25 | 8.45 | +35
| | 6.25 | 8.66 | +39
| | 12.5 | 12.7 | +2
| | 12.5 | 12.9 | +3
| | 25 | 27.2 | +9
| | 25 | 27.1 | +8
| | 50 | 57.2 | +14
| | 50 | 54.9 | +10
| | 100 | 99.4 | −1
| | 100 | 98.4 | −2
January 2, 2007 | January 2, 2007 | 6.25 | 6.47 | +4
| | 6.25 | 6.42 | +3
| | 12.5 | 12.4 | −1
| | 12.5 | 12.4 | −1
| | 25 | 24.8 | −1
| | 25 | 24.7 | −1
| | 50 | 49.0 | −2
| | 50 | 48.8 | −2
| | 100 | 97.1 | −3
| | 100 | 96.9 | −3
| February 15, 2007^b^ | 6.25 | 6.80 | +9
| | 6.25 | 6.94 | +11
| | 12.5 | 12.7 | +2
| | 12.5 | 12.9 | +3
| | 25 | 26.7 | +7
| | 25 | 29.0 | +16
| | 50 | 50.5 | +1
| | 50 | 51.8 | +4
| | 100 | 101 | +1
| | 100 | 103 | +3
| February 15, 2007^c^ | 6.25 | 6.90 | +10
| | 6.25 | 6.90 | +10
| | 12.5 | 13.0 | +4
| | 12.5 | 13.3 | +6
| | 25 | 29.4 | +18
| | 25 | 27.4 | +10
| | 50 | 51.5 | +3
| | 50 | 53.5 | +7
| | 100 | 100 | 0
| | 100 | 101 | +1
February 2, 2007 | February 6, 2007 | 6.25 | 6.33 | +1
| | 6.25 | 6.16 | −1
| | 12.5 | 12.4 | −1
| | 12.5 | 12.5 | 0
| | 25 | 24.9 | 0
| | 25 | 25.0 | 0
| | 50 | 48.9 | −2
| | 50 | 49.9 | 0
| | 100 | 100.8 | +1
| | 100 | 101.3 | +1
| March 20, 2007^b^ | 6.25 | 6.43 | +3
| | 6.25 | 6.61 | +6
| | 12.5 | 12.8 | +2
| | 12.5 | 12.6 | +1
| | 25 | 25.0 | 0
| | 25 | 25.2 | +1
| | 50 | 51.0 | +2
| | 50 | 51.4 | +3
| | 100 | 102 | −2
| | 100 | 99 | −1
| March 20, 2007^c^ | 6.25 | 6.49 | +4
| | 6.25 | 6.63 | +6
| | 12.5 | 12.9 | +3
| | 12.5 | 12.8 | +2
| | 25 | 25.6 | +2
| | 25 | 25.5 | +2
| | 50 | 52.1 | +4
| | 50 | 51.3 | +3
| | 100 | 100 | 0
| | 100 | 101 | +1

^a^ Results of duplicate analyses.

^b^ Animal room samples for rats.

^c^ Animal room samples for mice.

Figure F-1

Infrared Absorption Spectrum of OTNE

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of OTNE