# Appendix E Genetic Toxicology

Table E-1 Mutagenicity of OTNE in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | With 10% Rat S9
TA102 | 0 | 293 ± 6 | 396 ± 27
| 100 | 349 ± 11 | 349 ± 16
| 333 | 373 ± 14 | 434 ± 29
| 1,000 | 382 ± 18 | 352 ± 16
| 3,333 | 352 ± 4 | 322 ± 13
| 10,000 | 362 ± 20^b^ | 320 ± 9^b^
Trial summary | | Negative | Negative
Positive control^c^ | | 1,354 ± 12 | 1,495 ± 44
TA100 | 0 | 144 ± 6 | 152 ± 12
| 100 | 122 ± 6 | 153 ± 10
| 333 | 118 ± 8 | 129 ± 8
| 1,000 | 125 ± 8 | 115 ± 7
| 3,333 | 104 ± 3^b^ | 94 ± 1^b^
| 10,000 | 117 ± 2^b^ | 98 ± 8^b^
Trial summary | | Negative | Negative
Positive control | | 448 ± 9 | 917 ± 36
TA98 | 0 | 19 ± 1 | 29 ± 0
| 100 | 21 ± 1 | 34 ± 5
| 333 | 22 ± 1 | 21 ± 3
| 1,000 | 23 ± 2 | 29 ± 1
| 3,333 | 23 ± 1^b^ | 23 ± 3^b^
| 10,000 | 16 ± 1^b^ | 27 ± 2^b^
Trial summary | | Negative | Negative
Positive control | | 137 ± 21 | 441 ± 197

^a^ Study was performed at BioReliance Corporation using lot RAV0276433. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control. The detailed protocol is presented by Zeiger et al.^53^

^b^ Precipitate on plate.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and mitomycin-C (TA102). The positive control for metabolic activation with all strains was 2-aminoanthracene, except 2-aminoanthracene or sterigmatocystin was used for TA102.

Table E-2 Mutagenicity of OTNE in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 92 ± 6 | 90 ± 1 | 91 ± 11 | 103 ± 6
| 100 | 72 ± 5 | 50 ± 1 | 100 ± 5 | 111 ± 6
| 350 | 60 ± 8 | 54 ± 3 | 86 ± 8 | 73 ± 5
| 1,000 | 68 ± 1 | 57 ± 4 | 61 ± 6 | 51 ± 6
| 1,500 | 65 ± 3 | 56 ± 7 | 38 ± 8^b^ | 52 ± 4
| 3,000 | 65 ± 5 | 51 ± 1 | 45 ± 2^b^ | 50 ± 8
| 6,000 | 58 ± 3 | 57 ± 4 | 26 ± 5^c^ | 26 ± 3^c^
Trial summary | | Negative | Negative | Negative | Negative
Positive control^d^ | | 782 ± 23 | 793 ± 23 | 506 ± 14 | 452 ± 13
TA98
| 0 | 22 ± 1 | 16 ± 1 | 24 ± 3 | 30 ± 4
| 100 | 22 ± 4 | 15 ± 2 | 23 ± 1 | 29 ± 5
| 350 | 17 ± 7 | 20 ± 1 | 24 ± 2 | 25 ± 3
| 1,000 | 13 ± 3 | 14 ± 2 | 24 ± 1 | 25 ± 2
| 1,500 | 13 ± 1 | 17 ± 2 | 23 ± 2 | 28 ± 4
| 3,000 | 18 ± 3 | 23 ± 2 | 25 ± 4 | 23 ± 4
| 6,000 | 17 ± 3 | 22 ± 3 | 15 ± 4^e^ | 25 ± 2^e^
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 528 ± 30 | 639 ± 32 | 1,395 ± 26 | 1,419 ± 25
Escherichia coli WP2 uvrA/pKM101
| 0 | 155 ± 5 | 144 ± 4 | 222 ± 13 | 197 ± 9
| 100 | 148 ± 4 | 158 ± 6 | 222 ± 4 | 241 ± 1
| 350 | 171 ± 5 | 160 ± 14 | 190 ± 9 | 206 ± 12
| 1,000 | 146 ± 5 | 143 ± 4 | 170 ± 11 | 168 ± 9
| 1,500 | 141 ± 8 | 151 ± 2 | 160 ± 6 | 183 ± 9
| 3,000 | 142 ± 11 | 158 ± 3 | 148 ± 5 | 159 ± 10
| 6,000 | 158 ± 10 | 149 ± 9 | 146 ± 13^e^ | 157 ± 18^e^
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 3,171 ± 58 | 3,090 ± 59 | 1,598 ± 60 | 1,685 ± 63

^a^ Study was performed at ILS, Inc., using lot RAV0276433. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ Slight toxicity and precipitate on plate.

^d^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

^e^ Precipitate on plate.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Dermal Application of OTNE for Three Months^a^

| Dose (%) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^d^ | PCEs^b^ (%) | P Value^d^
Male
Vehicle control^e^ | 0 | 5 | 0.38 ± 0.06 | | 0.08 ± 0.01 | | 1.20 ± 0.07
OTNE | 6.25 | 5 | 0.43 ± 0.08 | 0.431 | 0.07 ± 0.01 | 0.980 | 1.18 ± 0.03 | 1.000
| 12.5 | 5 | 0.36 ± 0.03 | 0.509 | 0.04 ± 0.01 | 0.993 | 1.23 ± 0.03 | 1.000
| 25 | 5 | 0.65 ± 0.07 | 0.021 | 0.05 ± 0.00 | 0.996 | 1.29 ± 0.07 | 1.000
| 50 | 5 | 0.50 ± 0.06 | 0.022 | 0.05 ± 0.01 | 0.997 | 1.00 ± 0.08 | 0.022
| | | P = 0.045^f^ | | P = 0.963^f^ | | P = 0.025^f^
Untreated control | | 5 | 0.38 ± 0.04 | | 0.09 ± 0.01 | | 1.12 ± 0.05
OTNE | 100 | 5 | 0.43 ± 0.09 | 0.320 | 0.04 ± 0.01 | 0.969 | 1.11 ± 0.07 | 0.850
Untreated control | | 5 | 0.38 ± 0.04 | | 0.09 ± 0.01 | | 1.12 ± 0.05
Vehicle control | 0 | 5 | 0.38 ± 0.06 | 0.502 | 0.08 ± 0.01 | 0.621 | 1.20 ± 0.07 | 0.400
Female
Vehicle control | 0 | 5 | 0.58 ± 0.15 | | 0.08 ± 0.03 | | 0.79 ± 0.07
OTNE | 6.25 | 5 | 0.40 ± 0.06 | 0.690 | 0.04 ± 0.01 | 1.000 | 0.84 ± 0.12 | 1.000
| 12.5 | 5 | 0.55 ± 0.21 | 0.653 | 0.06 ± 0.02 | 1.000 | 1.07 ± 0.11 | 0.375
| 25 | 5 | 0.58 ± 0.06 | 0.688 | 0.06 ± 0.01 | 1.000 | 0.69 ± 0.04 | 1.000
| 50 | 5 | 0.52 ± 0.09 | 0.707 | 0.03 ± 0.00 | 1.000 | 0.70 ± 0.05 | 1.000
| | | P = 0.454^f^ | | P = 0.910^g^ | | P = 0.214^g^
Untreated control | | 5 | 0.53 ± 0.07 | | 0.07 ± 0.02 | | 0.96 ± 0.06
OTNE | 100 | 5 | 0.45 ± 0.05 | 0.677 | 0.10 ± 0.02 | 0.116 | 1.29 ± 0.34 | 0.465
Untreated control | | 5 | 0.53 ± 0.07 | | 0.07 ± 0.02 | | 0.96 ± 0.06
Vehicle control | 0 | 5 | 0.58 ± 0.15 | 0.385 | 0.08 ± 0.03 | 0.412 | 0.79 ± 0.07 | 0.112

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Dertinger et al.,^54^ MacGregor et al.,^55^ and Witt et al.^56^ PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison of 6.25%, 12.5%, 25%, and 50% groups with the vehicle control group, values are significant at P ≤ 0.025 by Williams’ test; 100% (neat) group with the untreated control group or vehicle control group with the untreated control group, values are significant at P ≤ 0.05 by Williams’ test.

^d^ Pairwise comparison with the vehicle control group, values are significant at P ≤ 0.025 by Williams’ test (6.25%, 12.5%, 25%, and 50% males) or Dunn’s test (6.25%, 12.5%, 25%, and 50% females); 100% (neat) group with the untreated control group or vehicle control group with the untreated control group, values are significant at P ≤ 0.05 by Williams’ test.

^e^ 95% ethanol.

^f^ Dose-related trend; significant at P ≤ 0.025 by linear regression.

^g^ Dose-related trend; significant at P ≤ 0.025 by Jonckheere’s test.

Table E-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Dermal Application of OTNE for Three Months^a^

| Dose (%) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Vehicle control^d^ | 0 | 5 | 2.42 ± 0.16 | | 1.47 ± 0.02 | | 1.46 ± 0.08
OTNE | 6.25 | 5 | 2.55 ± 0.24 | 0.397 | 1.48 ± 0.04 | 0.703 | 1.52 ± 0.12 | 0.620
| 12.5 | 5 | 2.78 ± 0.30 | 0.471 | 1.43 ± 0.04 | 0.787 | 1.58 ± 0.08 | 0.651
| 25 | 5 | 2.43 ± 0.20 | 0.501 | 1.39 ± 0.05 | 0.820 | 1.52 ± 0.04 | 0.695
| 50 | 5 | 2.24 ± 0.14 | 0.518 | 1.49 ± 0.02 | 0.477 | 1.47 ± 0.05 | 0.717
| | | P = 0.865^e^ | | P = 0.442 | | P = 0.851
Untreated control | | 5 | 2.66 ± 0.14 | | 1.45 ± 0.02 | | 1.60 ± 0.06
OTNE | 100 | 5 | 2.29 ± 0.15 | 0.805 | 1.59 ± 0.03 | 0.001 | 2.00 ± 0.20 | 0.066
Untreated control | | 5 | 2.66 ± 0.14 | | 1.45 ± 0.02 | | 1.60 ± 0.59
Vehicle control | 0 | 5 | 2.42 ± 0.16 | 0.707 | 1.47 ± 0.02 | 0.235 | 1.46 ± 0.08 | 0.190
Female
Vehicle control | 0 | 5 | 2.13 ± 0.12 | | 1.01 ± 0.02 | | 1.52 ± 0.12
OTNE | 6.25 | 5 | 1.76 ± 0.10 | 0.877 | 1.01 ± 0.02 | 0.472 | 1.51 ± 0.09 | 1.000
| 12.5 | 5 | 2.15 ± 0.05 | 0.887 | 1.07 ± 0.04 | 0.064 | 2.06 ± 0.13 | 0.053
| 25 | 5 | 1.95 ± 0.14 | 0.912 | 1.08 ± 0.02 | 0.039 | 1.84 ± 0.21 | 0.056
| 50 | 5 | 1.85 ± 0.12 | 0.924 | 1.15 ± 0.01 | 0.001 | 1.96 ± 0.14 | 0.045
| | | P = 0.856 | | P < 0.001 | | P = 0.050
Untreated control | | 5 | 1.98 ± 0.14 | | 1.03 ± 0.04 | | 1.08 ± 0.15
OTNE | 100 | 5 | 2.88 ± 0.23 | 0.005 | 1.27 ± 0.01 | <0.001 | 1.89 ± 0.25 | 0.031
Untreated control | | 5 | 1.98 ± 0.14 | | 1.03 ± 0.04 | | 1.08 ± 0.15
Vehicle control | 0 | 5 | 2.13 ± 0.12 | 0.230 | 1.01 ± 0.02 | 0.581 | 1.52 ± 0.12 | 0.048

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Dertinger et al.,^54^ MacGregor et al.,^55^ and Witt et al.^56^ PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison of 6.25%, 12.5%, 25%, and 50% groups with the vehicle control group, values are significant at P ≤ 0.025 by Williams’ test; 100% (neat) group with the untreated control group or vehicle control group with the untreated control group, values are significant at P ≤ 0.05 by Williams’ test.

^d^ 95% ethanol.

^e^ Dose-related trend; significant at P ≤ 0.025 by linear regression.