# Appendix D Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table D-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 25% | 50% | 100%
n | 10 | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 325 ± 6 | 318 ± 6 | 307 ± 8 | 302 ± 7 | 306 ± 7
L. Cauda epididymis | 0.1850 ± 0.0051 | 0.1884 ± 0.0066 | 0.1782 ± 0.0051 | 0.1736 ± 0.0087 | 0.1809 ± 0.0072
L. Epididymis | 0.4790 ± 0.0190 | 0.4457 ± 0.0145 | 0.4608 ± 0.0100 | 0.4580 ± 0.0202 | 0.4507 ± 0.0141
L. Testis | 1.5291 ± 0.0222 | 1.4998 ± 0.0315 | 1.5005 ± 0.0233 | 1.5015 ± 0.0340 | 1.5300 ± 0.0360
Spermatid measurements
Spermatid heads (10^6^/g testis) | 105.01 ± 5.31 | 129.89 ± 7.50 | 118.07 ± 10.87 | 122.10 ± 13.34 | 108.85 ± 6.97
Spermatid heads (10^6^/testis) | 160.52 ± 8.41 | 194.42 ± 11.31 | 177.51 ± 16.75 | 182.77 ± 19.24 | 167.21 ± 12.74
Epididymal spermatozoal measurements
Sperm motility (%) | 85.2 ± 3.4 | 80.5 ± 5.8 | 89.4 ± 2.1 | 87.5 ± 2.4 | 74.8 ± 9.0
Sperm (10^6^/g cauda epididymis) | 335.6 ± 14.4 | 326.8 ± 45.2 | 349.5 ± 20.2 | 321.7 ± 36.2 | 371.3 ± 30.7
Sperm (10^6^/cauda epididymis) | 62.1 ± 3.4 | 61.1 ± 8.3 | 61.8 ± 2.9 | 58.0 ± 7.0 | 66.2 ± 5.1

^a^ Data are presented as mean ± standard error. Differences between the vehicle control group and the 25% and 50% groups are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements). Differences between the untreated control group and the 100% group are not significant by a t-test (body and tissue weights) or Wilcoxon’s rank sum test (spermatid and epididymal spermatozoal measurements). Statistical comparisons between the two control groups are not presented.

Table D-2 Estrous Cycle Characterization for Female Rats in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 25% | 50% | 100%
Number weighed at necropsy | 10 | 10 | 10 | 10 | 10
Necropsy body wt (g) | 184 ± 4 | 187 ± 3 | 187 ± 4 | 184 ± 3 | 180 ± 3
Proportion of regular cycling females^b^ | 10/10 | 9/10 | 10/10 | 10/10 | 10/10
Estrous cycle length (days) | 5.0 ± 0.1 | 4.9 ± 0.2 | 4.8 ± 0.1 | 4.7 ± 0.2 | 4.9 ± 0.1
Estrous stages (% of cycle)
Diestrus | 60.0 | 61.3 | 53.1 | 53.1 | 59.4
Proestrus | 11.9 | 8.8 | 10.6 | 15.0 | 13.8
Estrus | 26.3 | 25.6 | 30.6 | 24.4 | 23.1
Metestrus | 0.0 | 0.0 | 0.0 | 0.0 | 0.0
Uncertain diagnosis | 1.9 | 4.4 | 5.6 | 7.5 | 3.8

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences between the vehicle control group and the 25% and 50% groups are not significant by Dunnett’s test (body weights) or Dunn’s test (estrous cycle length). Differences between the untreated control group and the 100% group are not significant by a t-test (body weights) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the respective control group and each dosed group indicated treated females did not spend significantly more time in a given estrous stage than did the respective control group. Statistical comparisons between the two control groups are not presented.

^b^ Number of females with a regular cycle/number of females cycling.

Table D-3 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 25% | 50% | 100%
n | 9 | 10 | 7 | 7 | 10
Weights (g)
Necropsy body wt | 37.8 ± 1.3 | 35.0 ± 0.6 | 32.2 ± 0.5** | 32.9 ± 0.5* | 32.2 ± 0.4^††^
L. Cauda epididymis | 0.0210 ± 0.0015 | 0.0196 ± 0.0011 | 0.0218 ± 0.0017 | 0.0252 ± 0.0041 | 0.0170 ± 0.0012^†^
L. Epididymis | 0.0515 ± 0.0040 | 0.0480 ± 0.0023 | 0.0615 ± 0.0068 | 0.0549 ± 0.0040 | 0.0435 ± 0.0021
L. Testis | 0.1119 ± 0.0022 | 0.1119 ± 0.0016 | 0.1114 ± 0.0041 | 0.1085 ± 0.0038 | 0.1052 ± 0.0025
Spermatid measurements
Spermatid heads (10^6^/g testis) | 214.10 ± 17.77 | 233.47 ± 16.49 | 252.91 ± 18.67 | 254.21 ± 16.20 | 234.12 ± 21.35
Spermatid heads (10^6^/testis) | 23.93 ± 1.97 | 26.21 ± 2.10 | 27.93 ± 1.79 | 27.57 ± 2.00 | 24.80 ± 2.40
Epididymal spermatozoal measurements
Sperm motility (%) | 90.8 ± 2.2 | 94.7 ± 0.8 | 91.0 ± 3.6 | 92.4 ± 1.9 | 80.6 ± 7.4
Sperm (10^6^/g cauda epididymis) | 169.9 ± 21.6 | 151.1 ± 11.2 | 144.3 ± 8.9 | 153.9 ± 29.2 | 112.2 ± 22.4
Sperm (10^6^/cauda epididymis) | 3.4 ± 0.3 | 2.9 ± 0.2 | 3.2 ± 0.4 | 3.5 ± 0.7 | 1.8 ± 0.3^††^

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

** P ≤ 0.01.

^†^ Significantly different (P ≤ 0.05) from the untreated control group by Wilcoxon’s rank sum test.

^††^ Significantly different (P ≤ 0.01) from the untreated control group by a t-test (body weights) or Wilcoxon’s rank sum test (sperm/cauda epididymis).

^a^ Data are presented as mean ± standard error. Differences between the vehicle control group and the 25% and 50% groups are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements). Differences between the untreated control group and the 100% group are not significant by a t-test (tissue weights) or Wilcoxon’s rank sum test (spermatid measurements, sperm motility, and sperm/g cauda epididymis). Statistical comparisons between the two control groups are not presented.

Table D-4 Estrous Cycle Characterization for Female Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 25% | 50% | 100%
Number weighed at necropsy | 10 | 10 | 10 | 10 | 10
Necropsy body wt (g) | 28.5 ± 0.7 | 29.5 ± 0.7 | 28.9 ± 0.3 | 29.2 ± 0.4 | 29.4 ± 0.3
Proportion of regular cycling females^b^ | 9/10 | 10/10 | 10/10 | 10/10 | 9/10
Estrous cycle length (days) | 4.0 ± 0.2 | 4.5 ± 0.2 | 4.6 ± 0.2 | 4.5 ± 0.2 | 5.2 ± 0.3^††^
Estrous stages (% of cycle)
Diestrus | 38.8 | 38.8 | 31.3 | 33.8 | 37.5
Proestrus | 0.0 | 0.0 | 1.3 | 0.6 | 0.0
Estrus | 38.1 | 43.1 | 51.3 | 56.3 | 53.1
Metestrus | 15.0 | 11.9 | 10.0 | 6.3 | 6.9
Uncertain diagnosis | 8.1 | 6.3 | 6.3 | 3.1 | 2.5

^††^ Significantly different (P ≤ 0.01) from the untreated control group by Dunn’s test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences between the vehicle control group and the 25% and 50% groups are not significant by Dunnett’s test (body weights) or Dunn’s test (estrous cycle length). Differences between the untreated control group and the 100% group are not significant by a t-test (body weights). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the respective control group and each dosed group indicated the probability of extended estrus was significantly higher in the dosed groups than the respective control groups. Statistical comparisons between the two control groups are not presented.

^b^ Number of females with a regular cycle/number of females cycling.