# Appendix C Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table C-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
n | 10 | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 324 ± 6 | 318 ± 6 | 308 ± 9 | 293 ± 5 | 307 ± 8 | 302 ± 7 | 306 ± 7
Heart
Absolute | 1.02 ± 0.02 | 1.02 ± 0.02 | 0.93 ± 0.01* | 0.94 ± 0.03 | 0.99 ± 0.03 | 0.98 ± 0.03 | 0.98 ± 0.02
Relative | 3.16 ± 0.04 | 3.22 ± 0.03 | 3.04 ± 0.06 | 3.21 ± 0.07 | 3.23 ± 0.09 | 3.26 ± 0.06 | 3.19 ± 0.05
R. Kidney
Absolute | 1.19 ± 0.03 | 1.20 ± 0.02 | 1.14 ± 0.03 | 1.11 ± 0.02 | 1.14 ± 0.03 | 1.18 ± 0.03 | 1.24 ± 0.03
Relative | 3.66 ± 0.05 | 3.77 ± 0.06 | 3.71 ± 0.06 | 3.80 ± 0.04 | 3.71 ± 0.06 | 3.92 ± 0.07 | 4.04 ± 0.05^††^
Liver
Absolute | 13.62 ± 0.54 | 13.60 ± 0.48 | 12.81 ± 0.44 | 12.73 ± 0.50 | 13.33 ± 0.46 | 14.57 ± 0.74 | 15.93 ± 0.65^†^
Relative | 41.95 ± 1.17 | 42.77 ± 1.16 | 41.62 ± 0.95 | 43.55 ± 1.84 | 43.48 ± 1.38 | 48.04 ± 1.64* | 52.12 ± 1.83^††^
Lung
Absolute | 1.78 ± 0.11 | 1.72 ± 0.07 | 1.67 ± 0.10 | 1.60 ± 0.05 | 1.70 ± 0.08 | 1.57 ± 0.05 | 1.60 ± 0.05
Relative | 5.47 ± 0.27 | 5.40 ± 0.19 | 5.39 ± 0.21 | 5.49 ± 0.22 | 5.52 ± 0.19 | 5.19 ± 0.11 | 5.29 ± 0.16
R. Testis
Absolute | 1.543 ± 0.102 | 1.453 ± 0.020 | 1.427 ± 0.035 | 1.409 ± 0.024 | 1.478 ± 0.029 | 1.452 ± 0.032 | 1.467 ± 0.025
Relative | 4.762 ± 0.301 | 4.580 ± 0.047 | 4.645 ± 0.081 | 4.816 ± 0.083 | 4.824 ± 0.079 | 4.831 ± 0.141 | 4.806 ± 0.058
Thymus
Absolute | 0.347 ± 0.056 | 0.302 ± 0.033 | 0.394 ± 0.075 | 0.271 ± 0.015 | 0.274 ± 0.015 | 0.303 ± 0.026 | 0.359 ± 0.074
Relative | 1.068 ± 0.172 | 0.943 ± 0.094 | 1.280 ± 0.248 | 0.921 ± 0.044 | 0.896 ± 0.052 | 0.990 ± 0.065 | 1.155 ± 0.224
Female
Necropsy body wt | 184 ± 4 | 187 ± 3 | 188 ± 2 | 184 ± 4 | 187 ± 4 | 184 ± 3 | 180 ± 3
Heart
Absolute | 0.71 ± 0.03 | 0.73 ± 0.01 | 0.72 ± 0.01 | 0.71 ± 0.02 | 0.74 ± 0.02 | 0.73 ± 0.01 | 0.73 ± 0.02
Relative | 3.86 ± 0.12 | 3.91 ± 0.04 | 3.83 ± 0.05 | 3.87 ± 0.09 | 3.97 ± 0.11 | 3.95 ± 0.08 | 4.06 ± 0.07
R. Kidney
Absolute | 0.74 ± 0.02 | 0.78 ± 0.02 | 0.78 ± 0.02 | 0.77 ± 0.02 | 0.78 ± 0.02 | 0.80 ± 0.01 | 0.78 ± 0.02
Relative | 4.00 ± 0.06 | 4.18 ± 0.08 | 4.13 ± 0.07 | 4.18 ± 0.07 | 4.18 ± 0.09 | 4.32 ± 0.03 | 4.34 ± 0.07^††^
Liver
Absolute | 6.50 ± 0.33 | 6.99 ± 0.21 | 6.89 ± 0.19 | 7.09 ± 0.27 | 7.51 ± 0.20 | 7.78 ± 0.27*^b^ | 8.24 ± 0.18^††^
Relative | 35.29 ± 1.42 | 37.44 ± 0.67 | 36.60 ± 0.92 | 38.52 ± 1.40 | 40.09 ± 0.65 | 41.93 ± 1.35**^b^ | 46.29 ± 1.02^††^
Lung
Absolute | 1.14 ± 0.04 | 1.13 ± 0.04 | 1.11 ± 0.04 | 1.26 ± 0.11 | 1.21 ± 0.06 | 1.13 ± 0.04 | 1.12 ± 0.06
Relative | 6.20 ± 0.20 | 6.07 ± 0.27 | 5.89 ± 0.18 | 6.77 ± 0.50 | 6.44 ± 0.27 | 6.14 ± 0.25 | 6.20 ± 0.34
Thymus
Absolute | 0.292 ± 0.017 | 0.252 ± 0.020 | 0.249 ± 0.020 | 0.252 ± 0.017 | 0.252 ± 0.013 | 0.265 ± 0.016 | 0.255 ± 0.008
Relative | 1.598 ± 0.105 | 1.343 ± 0.095 | 1.320 ± 0.098 | 1.361 ± 0.084 | 1.347 ± 0.063 | 1.442 ± 0.094 | 1.421 ± 0.047

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s or Williams’ test.

** P ≤ 0.01.

† Significantly different (P ≤ 0.05) from the untreated control group by a t-test.

†† P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Statistical comparisons between the two control groups are not presented.

^b^ n = 9.

Table C-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
n | 10 | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 37.7 ± 1.2 | 35.0 ± 0.6 | 32.2 ± 0.4** | 33.7 ± 1.0 | 32.0 ± 0.4** | 32.5 ± 0.5* | 32.2 ± 0.4^††^
Heart
Absolute | 0.19 ± 0.01 | 0.18 ± 0.00 | 0.17 ± 0.00 | 0.17 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.01 | 0.19 ± 0.00
Relative | 5.06 ± 0.21 | 4.99 ± 0.09 | 5.27 ± 0.16 | 5.16 ± 0.14 | 5.71 ± 0.17* | 5.46 ± 0.24 | 5.74 ± 0.10^†^
R. Kidney
Absolute | 0.35 ± 0.02 | 0.35 ± 0.01 | 0.32 ± 0.01 | 0.34 ± 0.01 | 0.34 ± 0.01 | 0.33 ± 0.01 | 0.33 ± 0.02
Relative | 9.24 ± 0.40 | 10.00 ± 0.21 | 9.98 ± 0.20 | 10.27 ± 0.22 | 10.54 ± 0.34 | 10.09 ± 0.18 | 10.20 ± 0.63
Liver
Absolute | 1.64 ± 0.05 | 1.60 ± 0.05 | 1.68 ± 0.07 | 1.82 ± 0.09* | 1.99 ± 0.09** | 2.12 ± 0.03** | 2.66 ± 0.07^††^
Relative | 43.79 ± 1.34 | 45.72 ± 1.29 | 51.98 ± 1.96* | 54.09 ± 2.20** | 62.10 ± 2.99** | 65.35 ± 1.52** | 82.51 ± 1.92^††^
Lung
Absolute | 0.29 ± 0.02 | 0.30 ± 0.02 | 0.29 ± 0.02 | 0.31 ± 0.02 | 0.27 ± 0.02 | 0.26 ± 0.02 | 0.27 ± 0.02
Relative | 7.69 ± 0.38 | 8.49 ± 0.51 | 8.98 ± 0.59 | 9.34 ± 0.60 | 8.45 ± 0.63 | 8.12 ± 0.48 | 8.44 ± 0.50
R. Testis
Absolute | 0.127 ± 0.004 | 0.128 ± 0.002 | 0.120 ± 0.005 | 0.127 ± 0.004 | 0.120 ± 0.002 | 0.115 ± 0.004* | 0.119 ± 0.004
Relative | 3.397 ± 0.131 | 3.661 ± 0.086 | 3.734 ± 0.156 | 3.780 ± 0.103 | 3.760 ± 0.072 | 3.544 ± 0.078 | 3.693 ± 0.121
Thymus
Absolute | 0.050 ± 0.003 | 0.050 ± 0.003 | 0.043 ± 0.002 | 0.042 ± 0.004 | 0.041 ± 0.003 | 0.041 ± 0.002 | 0.039 ± 0.003^†^
Relative | 1.338 ± 0.082 | 1.424 ± 0.098 | 1.346 ± 0.073 | 1.233 ± 0.078 | 1.268 ± 0.082 | 1.273 ± 0.075 | 1.202 ± 0.078
Female
Necropsy body wt | 28.5 ± 0.7 | 29.5 ± 0.7 | 30.1 ± 0.7 | 29.2 ± 0.6 | 28.9 ± 0.3 | 29.2 ± 0.4 | 29.4 ± 0.3
Heart
Absolute | 0.14 ± 0.00 | 0.15 ± 0.01 | 0.15 ± 0.00 | 0.16 ± 0.01 | 0.16 ± 0.00 | 0.17 ± 0.00* | 0.16 ± 0.01^††^
Relative | 4.85 ± 0.08 | 5.08 ± 0.18 | 5.12 ± 0.13 | 5.36 ± 0.20 | 5.47 ± 0.09 | 5.68 ± 0.16* | 5.55 ± 0.16^††^
R. Kidney
Absolute | 0.21 ± 0.01 | 0.22 ± 0.01 | 0.21 ± 0.00 | 0.23 ± 0.01 | 0.22 ± 0.01 | 0.24 ± 0.01 | 0.23 ± 0.01
Relative | 7.51 ± 0.20 | 7.39 ± 0.21 | 7.13 ± 0.19 | 8.00 ± 0.32 | 7.57 ± 0.23 | 8.11 ± 0.23 | 7.84 ± 0.21
Liver
Absolute | 1.28 ± 0.04 | 1.37 ± 0.05 | 1.52 ± 0.04* | 1.65 ± 0.04** | 1.69 ± 0.03** | 2.04 ± 0.05** | 2.46 ± 0.07^††^
Relative | 45.04 ± 1.03 | 46.48 ± 1.46 | 50.45 ± 0.76* | 56.53 ± 1.22** | 58.35 ± 0.61** | 69.96 ± 1.26** | 83.54 ± 2.31^††^
Lung
Absolute | 0.30 ± 0.02 | 0.29 ± 0.02 | 0.26 ± 0.01 | 0.32 ± 0.02 | 0.27 ± 0.03 | 0.26 ± 0.02 | 0.24 ± 0.02
Relative | 10.41 ± 0.74 | 9.86 ± 0.75 | 8.71 ± 0.52 | 10.91 ± 0.76 | 9.44 ± 0.85 | 8.91 ± 0.54 | 8.22 ± 0.69^†^
Thymus
Absolute | 0.056 ± 0.002 | 0.058 ± 0.003 | 0.057 ± 0.002 | 0.053 ± 0.003 | 0.049 ± 0.004 | 0.052 ± 0.002 | 0.046 ± 0.002^††^
Relative | 1.982 ± 0.056 | 1.966 ± 0.102 | 1.924 ± 0.095 | 1.815 ± 0.075 | 1.706 ± 0.137 | 1.766 ± 0.078 | 1.548 ± 0.090^††^

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s or Williams’ test.

** P ≤ 0.01.

^†^ Significantly different (P ≤ 0.05) from the untreated control group by a t-test.

^††^ P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Statistical comparisons between the two control groups are not presented.