# Appendix B Clinical Pathology and Liver Toxicity Results

Table B-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | | 6.25% | 12.5% | 25% | | 50% | 100%
Male
Hematology
n
Day 3 | 9 | 10 | | 9 | 10 | 9 | | 10 | 10
Day 23 | 10 | 10 | | 9 | 10 | 10 | | 9 | 10
Week 13 | 10 | 10 | | 10 | 10 | 10 | | 10 | 9
Hematocrit (auto) (%)
Day 3 | 41.9 ± 0.6 | 41.5 ± 0.6 | | 40.5 ± 1.5 | 41.7 ± 0.5 | 40.4 ± 1.2 | | 40.5 ± 1.3 | 42.0 ± 0.3
Day 23 | 42.4 ± 0.6 | 42.1 ± 0.5 | | 43.5 ± 0.4 | 42.5 ± 0.8 | 41.8 ± 0.7 | | 43.2 ± 0.3 | 43.7 ± 0.3
Week 13 | 48.3 ± 0.4 | 48.1 ± 1.2 | | 47.8 ± 0.4 | 48.0 ± 0.5 | 48.5 ± 0.7 | | 47.6 ± 0.7 | 47.2 ± 0.5
Hematocrit (spun) (%)
Day 3 | 48.3 ± 0.5 | 48.1 ± 0.5 | | 49.2 ± 1.0 | 49.0 ± 0.6 | 48.3 ± 0.8 | | 48.5 ± 0.8 | 49.2 ± 0.4
Day 23 | 50.7 ± 0.5 | 49.4 ± 0.5 | | 51.4 ± 0.5* | 50.4 ± 0.7 | 50.1 ± 0.7 | | 51.1 ± 0.4 | 51.3 ± 0.5
Week 13 | 50.5 ± 0.6 | 51.2 ± 0.4 | | 50.4 ± 0.4 | 50.8 ± 0.4 | 51.0 ± 0.4 | | 50.7 ± 0.4 | 50.2 ± 0.5
Hemoglobin (g/dL)
Day 3 | 13.7 ± 0.2 | 13.5 ± 0.2 | | 13.3 ± 0.5 | 13.7 ± 0.1 | 13.3 ± 0.4 | | 13.3 ± 0.4 | 13.8 ± 0.1
Day 23 | 14.2 ± 0.2 | 14.1 ± 0.2 | | 14.6 ± 0.1 | 14.2 ± 0.3 | 14.1 ± 0.2 | | 14.5 ± 0.1 | 14.5 ± 0.1
Week 13 | 16.1 ± 0.1 | 15.9 ± 0.4 | | 16.0 ± 0.1 | 16.0 ± 0.2 | 16.2 ± 0.2 | | 15.9 ± 0.2 | 15.8 ± 0.2
Erythrocytes (10^6^/µL)
Day 3 | 7.23 ± 0.09 | 7.08 ± 0.10 | | 6.97 ± 0.23 | 7.14 ± 0.09 | 6.94 ± 0.19 | | 6.95 ± 0.20 | 7.19 ± 0.05
Day 23 | 7.66 ± 0.10 | 7.62 ± 0.08 | | 7.79 ± 0.08 | 7.51 ± 0.17 | 7.53 ± 0.11 | | 7.74 ± 0.08 | 7.83 ± 0.07
Week 13 | 9.64 ± 0.08 | 9.66 ± 0.26 | | 9.47 ± 0.10 | 9.55 ± 0.09 | 9.69 ± 0.13 | | 9.49 ± 0.14 | 9.51 ± 0.11
Erythrocyte distribution width (%)
Day 3 | 15.50 ± 0.38 | 15.19 ± 0.26 | | 16.19 ± 0.32 | 15.49 ± 0.36 | 16.73 ± 0.31* | | 16.01 ± 0.39 | 15.91 ± 0.47
Day 23 | 13.29 ± 0.13 | 13.25 ± 0.19 | | 13.03 ± 0.10 | 13.52 ± 0.37 | 13.33 ± 0.13 | | 12.87 ± 0.08 | 13.50 ± 0.08
Week 13 | 12.83 ± 0.13 | 13.14 ± 0.11 | | 12.78 ± 0.11 | 12.77 ± 0.14 | 12.99 ± 0.08 | | 13.08 ± 0.18 | 13.01 ± 0.08
Reticulocytes (%)
Day 3 | 3.99 ± 0.26 | 4.19 ± 0.24 | | 4.02 ± 0.17 | 4.42 ± 0.16 | 4.19 ± 0.12 | | 4.15 ± 0.40 | 4.58 ± 0.29
Day 23 | 3.48 ± 0.21 | 3.81 ± 0.25 | | 2.94 ± 0.15* | 3.48 ± 0.22 | 3.16 ± 0.11 | | 3.47 ± 0.16 | 3.46 ± 0.15
Week 13 | 2.86 ± 0.23 | 2.92 ± 0.21 | | 3.07 ± 0.18 | 3.02 ± 0.13 | 3.18 ± 0.12 | | 3.00 ± 0.17 | 2.92 ± 0.10
Reticulocytes (10^3^/µL)
Day 3 | 288 ± 18 | 296 ± 16 | | 279 ± 13 | 316 ± 14 | 291 ± 12 | | 286 ± 26 | 329 ± 20
Day 23 | 265 ± 14 | 292 ± 21 | | 230 ± 13 | 258 ± 11 | 238 ± 11 | | 268 ± 12 | 271 ± 13
Week 13 | 276 ± 22 | 282 ± 21 | | 291 ± 16 | 288 ± 12 | 308 ± 12 | | 284 ± 15 | 278 ± 11
Nucleated erythrocytes (/100 leukocytes)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL)
Day 3 | 58.0 ± 0.3 | 58.5 ± 0.2 | | 58.0 ± 0.4 | 58.4 ± 0.3 | 58.3 ± 0.2 | | 58.2 ± 0.3 | 58.3 ± 0.3
Day 23 | 55.3 ± 0.2 | 55.2 ± 0.2 | | 55.7 ± 0.2 | 56.6 ± 0.6 | 55.6 ± 0.3 | | 55.7 ± 0.2 | 55.9 ± 0.4
Week 13 | 50.1 ± 0.2 | 49.8 ± 0.1 | | 50.5 ± 0.2 | 50.1 ± 0.2 | 50.1 ± 0.2 | | 50.1 ± 0.3 | 49.7 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 18.9 ± 0.1 | 19.1 ± 0.1 | | 19.1 ± 0.1 | 19.2 ± 0.1 | 19.1 ± 0.1 | | 19.1 ± 0.1 | 19.2 ± 0.1
Day 23 | 18.5 ± 0.1 | 18.5 ± 0.1 | | 18.7 ± 0.1 | 18.8 ± 0.1 | 18.7 ± 0.1 | | 18.7 ± 0.1 | 18.5 ± 0.1
Week 13 | 16.7 ± 0.1 | 16.5 ± 0.1 | | 16.9 ± 0.1** | 16.8 ± 0.1* | 16.7 ± 0.1 | | 16.7 ± 0.1 | 16.6 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 32.6 ± 0.1 | 32.6 ± 0.1 | | 32.9 ± 0.2 | 32.7 ± 0.1 | 32.9 ± 0.2 | | 32.9 ± 0.1 | 32.9 ± 0.1
Day 23 | 33.5 ± 0.1 | 33.6 ± 0.1 | | 33.5 ± 0.1 | 33.3 ± 0.1 | 33.6 ± 0.1 | | 33.6 ± 0.1 | 33.2 ± 0.1^†^
Week 13 | 33.3 ± 0.1 | 33.1 ± 0.1 | | 33.5 ± 0.1* | 33.4 ± 0.1 | 33.4 ± 0.1 | | 33.5 ± 0.1* | 33.4 ± 0.0
Platelets (10^3^/µL)
Day 3 | 828 ± 23 | 806 ± 17 | | 849 ± 46 | 830 ± 12 | 843 ± 28 | | 831 ± 15 | 813 ± 25
Day 23 | 748 ± 14 | 764 ± 15 | | 756 ± 12 | 782 ± 39 | 786 ± 46 | | 773 ± 20 | 791 ± 15^†^
Week 13 | 632 ± 17 | 632 ± 25 | | 602 ± 13 | 610 ± 21 | 664 ± 12 | | 659 ± 14 | 715 ± 18^††^
Mean platelet volume (fL)
Day 3 | 6.811 ± 0.070 | 6.710 ± 0.098 | | 7.267 ± 0.365 | 6.850 ± 0.105 | 7.111 ± 0.063* | | 6.920 ± 0.107 | 7.040 ± 0.120
Day 23 | 6.290 ± 0.081 | 6.240 ± 0.070 | | 6.244 ± 0.112 | 6.250 ± 0.090 | 6.420 ± 0.073 | | 6.622 ± 0.213 | 6.440 ± 0.088
Week 13 | 6.310 ± 0.050 | 6.440 ± 0.065 | | 6.290 ± 0.043 | 6.520 ± 0.077 | 6.460 ± 0.064 | | 6.460 ± 0.052 | 6.589 ± 0.101^†^
Leukocytes (10^3^/µL)
Day 3 | 9.16 ± 0.60 | 8.88 ± 0.40 | | 8.81 ± 0.43 | 10.29 ± 0.36* | 8.28 ± 0.68 | | 8.88 ± 0.40 | 8.98 ± 0.31
Day 23 | 10.49 ± 0.47 | 10.39 ± 0.41 | | 10.81 ± 0.41 | 11.64 ± 1.12 | 10.35 ± 0.34 | | 10.00 ± 0.32 | 10.89 ± 0.35
Week 13 | 9.55 ± 0.46 | 10.13 ± 0.45 | | 9.26 ± 0.71 | 9.80 ± 0.48 | 9.38 ± 0.37 | | 9.96 ± 0.33 | 10.98 ± 0.38^†^
Segmented neutrophils (10^3^/µL)
Day 3 | 1.71 ± 0.15 | 1.80 ± 0.09 | | 1.46 ± 0.12 | 2.02 ± 0.11 | 1.57 ± 0.17 | | 1.69 ± 0.12 | 1.66 ± 0.11
Day 23 | 2.57 ± 0.12 | 2.47 ± 0.17 | | 2.46 ± 0.15 | 3.08 ± 0.64 | 2.42 ± 0.13 | | 2.12 ± 0.15 | 2.73 ± 0.14
Week 13 | 2.44 ± 0.20 | 2.57 ± 0.19 | | 2.42 ± 0.18 | 2.60 ± 0.12 | 2.42 ± 0.15 | | 2.84 ± 0.15 | 2.95 ± 0.16
Bands (10^3^/µL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Metamyelocytes (10^3^/µL)
Day 3 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Week 13 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Myelocytes (10^3^/µL)
Day 3 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Week 13 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Lymphocytes (10^3^/µL)
Day 3 | 7.03 ± 0.42 | 6.69 ± 0.34 | | 7.00 ± 0.40 | 7.78 ± 0.24 | 6.35 ± 0.52 | | 6.75 ± 0.29 | 6.96 ± 0.22
Day 23 | 7.43 ± 0.35 | 7.47 ± 0.23 | | 7.85 ± 0.24 | 8.00 ± 0.52 | 7.41 ± 0.43 | | 7.46 ± 0.18 | 7.60 ± 0.25
Week 13 | 6.61 ± 0.30 | 7.05 ± 0.36 | | 6.37 ± 0.54 | 6.73 ± 0.42 | 6.48 ± 0.26 | | 6.61 ± 0.37 | 7.37 ± 0.29
Atypical lymphocytes (10^3^/µL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Monocytes (10^3^/µL)
Day 3 | 0.22 ± 0.03 | 0.21 ± 0.01 | | 0.19 ± 0.03 | 0.27 ± 0.02 | 0.20 ± 0.03 | | 0.20 ± 0.02 | 0.20 ± 0.01
Day 23 | 0.23 ± 0.02 | 0.20 ± 0.02 | | 0.24 ± 0.02 | 0.28 ± 0.06 | 0.27 ± 0.05 | | 0.17 ± 0.01 | 0.26 ± 0.02
Week 13 | 0.24 ± 0.04 | 0.25 ± 0.03 | | 0.22 ± 0.02 | 0.23 ± 0.02 | 0.24 ± 0.03 | | 0.26 ± 0.02 | 0.32 ± 0.04
Basophils (10^3^/µL)
Day 3 | 0.153 ± 0.021 | 0.144 ± 0.014 | | 0.132 ± 0.013 | 0.179 ± 0.015 | 0.122 ± 0.017 | | 0.194 ± 0.022 | 0.137 ± 0.013
Day 23 | 0.187 ± 0.014 | 0.175 ± 0.012 | | 0.201 ± 0.016 | 0.212 ± 0.030 | 0.178 ± 0.014 | | 0.173 ± 0.016 | 0.215 ± 0.012
Week 13 | 0.162 ± 0.018 | 0.190 ± 0.018 | | 0.169 ± 0.025 | 0.169 ± 0.017 | 0.170 ± 0.012 | | 0.175 ± 0.018 | 0.240 ± 0.021^†^
Eosinophils (10^3^/µL)
Day 3 | 0.04 ± 0.01 | 0.04 ± 0.01 | | 0.02 ± 0.00 | 0.05 ± 0.01 | 0.03 ± 0.00 | | 0.05 ± 0.01 | 0.03 ± 0.01
Day 23 | 0.07 ± 0.01 | 0.08 ± 0.01 | | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | | 0.07 ± 0.00 | 0.08 ± 0.01
Week 13 | 0.09 ± 0.01 | 0.08 ± 0.01 | | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | | 0.08 ± 0.01 | 0.10 ± 0.01
Clinical Chemistry
n | 10 | 10 | | 10 | 10 | 10 | | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 13.6 ± 1.1 | 12.9 ± 0.4 | | 14.2 ± 0.7 | 13.8 ± 0.7 | 12.9 ± 0.7 | | 12.7 ± 0.4 | 12.0 ± 0.4
Day 23 | 14.3 ± 0.7 | 15.2 ± 0.7 | | 14.0 ± 0.8 | 14.8 ± 0.6 | 13.9 ± 0.7 | | 14.8 ± 0.5 | 14.7 ± 0.4
Week 13 | 18.9 ± 0.6 | 18.9 ± 0.4 | | 18.0 ± 0.5 | 19.9 ± 0.6 | 19.4 ± 0.6 | | 19.0 ± 0.6 | 19.2 ± 0.4
Creatinine (mg/dL)
Day 3 | 0.58 ± 0.01 | 0.59 ± 0.01 | | 0.60 ± 0.00 | 0.60 ± 0.01 | 0.57 ± 0.02 | | 0.60 ± 0.00 | 0.60 ± 0.00
Day 23 | 0.62 ± 0.01 | 0.62 ± 0.01 | | 0.61 ± 0.01 | 0.60 ± 0.01 | 0.62 ± 0.01 | | 0.65 ± 0.02 | 0.66 ± 0.02
Week 13 | 0.71 ± 0.01 | 0.72 ± 0.01 | | 0.74 ± 0.02 | 0.74 ± 0.02 | 0.78 ± 0.01** | | 0.79 ± 0.02** | 0.82 ± 0.01^††^
Total protein (g/dL)
Day 3 | 5.8 ± 0.1 | 5.6 ± 0.1 | | 5.8 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | | 5.6 ± 0.1 | 5.6 ± 0.1^†^
Day 23 | 6.1 ± 0.1 | 6.2 ± 0.1 | | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.1 ± 0.1 | | 6.2 ± 0.1 | 6.3 ± 0.1
Week 13 | 7.7 ± 0.1 | 7.7 ± 0.1 | | 7.6 ± 0.1 | 7.6 ± 0.1 | 7.8 ± 0.1 | | 7.7 ± 0.1 | 7.8 ± 0.1
Albumin (g/dL)
Day 3 | 3.6 ± 0.0 | 3.5 ± 0.0 | | 3.6 ± 0.0 | 3.6 ± 0.0 | 3.5 ± 0.0 | | 3.5 ± 0.0 | 3.5 ± 0.0^†^
Day 23 | 3.7 ± 0.0 | 3.7 ± 0.0 | | 3.7 ± 0.0 | 3.6 ± 0.1 | 3.7 ± 0.0 | | 3.7 ± 0.0 | 3.7 ± 0.0
Week 13 | 4.1 ± 0.0 | 4.1 ± 0.0 | | 4.0 ± 0.0 | 4.1 ± 0.0 | 4.1 ± 0.0 | | 4.1 ± 0.1 | 4.1 ± 0.0
Alanine aminotransferase (IU/L)
Day 3 | 81 ± 2 | 80 ± 3 | | 78 ± 3 | 79 ± 2 | 77 ± 2 | | 80 ± 2 | 81 ± 2
Day 23 | 54 ± 1 | 62 ± 4 | | 56 ± 2 | 54 ± 1 | 123 ± 71* | | 51 ± 1** | 52 ± 2
Week 13 | 88 ± 4 | 91 ± 8 | | 69 ± 2** | 80 ± 4* | 67 ± 2** | | 61 ± 2** | 54 ± 1^††^
Alkaline phosphatase (IU/L)
Day 3 | 710 ± 7 | 695 ± 12 | | 694 ± 13 | 697 ± 16 | 675 ± 11 | | 700 ± 13 | 663 ± 9^††^
Day 23 | 564 ± 13 | 525 ± 11 | | 529 ± 11 | 515 ± 19 | 475 ± 23 | | 475 ± 11* | 477 ± 9^††^
Week 13 | 349 ± 9 | 373 ± 10 | | 326 ± 11* | 346 ± 11* | 322 ± 7** | | 270 ± 19** | 268 ± 5^††^
Creatine kinase (IU/L)
Day 3 | 953 ± 88 | 916 ± 83 | | 905 ± 95 | 907 ± 70 | 992 ± 114 | | 733 ± 44 | 748 ± 68
Day 23 | 772 ± 123 | 526 ± 89^b^ | | 964 ± 372 | 587 ± 78 | 597 ± 80 | | 825 ± 137 | 650 ± 87
Week 13 | 224 ± 26 | 261 ± 34 | | 346 ± 48 | 228 ± 18 | 282 ± 43 | | 281 ± 48 | 336 ± 56
Sorbitol dehydrogenase (IU/L)
Day 3 | 28 ± 2 | 34 ± 4 | | 37 ± 3 | 36 ± 4 | 29 ± 4 | | 34 ± 4 | 32 ± 5
Day 23 | 32 ± 4 | 35 ± 4 | | 37 ± 4 | 31 ± 4 | 57 ± 20 | | 29 ± 4 | 33 ± 5
Week 13 | 56 ± 3 | 52 ± 3 | | 44 ± 2 | 53 ± 2 | 52 ± 2 | | 50 ± 3 | 45 ± 4^†^
Bile acids (µmol/L)
Day 3 | 57.0 ± 5.8 | 51.2 ± 6.7 | | 39.9 ± 5.3 | 50.2 ± 6.8 | 51.3 ± 6.8 | | 48.4 ± 6.8 | 48.6 ± 7.5
Day 23 | 51.6 ± 5.1 | 55.6 ± 4.5 | | 56.2 ± 3.3 | 53.2 ± 3.9 | 43.6 ± 3.2* | | 44.0 ± 3.7* | 47.1 ± 4.1
Week 13 | 8.2 ± 0.9 | 10.5 ± 1.9 | | 8.0 ± 0.8 | 8.5 ± 1.7 | 5.8 ± 0.9** | | 5.7 ± 0.7** | 8.2 ± 1.1
Female
Hematology
n
Day 3 | 10 | 10 | | 10 | 10 | 10 | | 10 | 10
Day 23 | 9 | 9 | | 9 | 9 | 9 | | 10 | 9
Week 13 | 10 | 10 | | 10 | 10 | 10 | | 10 | 10
Hematocrit (auto) (%)
Day 3 | 42.7 ± 0.4 | 42.6 ± 0.8 | | 42.3 ± 0.9 | 42.0 ± 0.6 | 42.0 ± 0.5 | | 42.3 ± 0.6 | 41.2 ± 0.6
Day 23 | 43.9 ± 0.9 | 43.0 ± 0.6 | | 43.4 ± 0.4 | 44.7 ± 0.5 | 44.1 ± 0.6 | | 43.4 ± 0.4 | 44.0 ± 0.6
Week 13 | 44.3 ± 0.6 | 45.4 ± 0.5 | | 46.3 ± 1.4 | 45.0 ± 0.6 | 43.8 ± 0.4 | | 43.9 ± 0.5 | 42.5 ± 0.4^†^
Hematocrit (spun) (%)
Day 3 | 49.4 ± 0.4 | 49.1 ± 0.8 | | 49.3 ± 0.9 | 48.9 ± 0.6 | 49.0 ± 0.6 | | 49.6 ± 0.8 | 48.4 ± 0.6
Day 23 | 53.3 ± 1.2 | 52.4 ± 0.8 | | 53.4 ± 1.2 | 53.7 ± 0.8 | 54.2 ± 1.2 | | 52.5 ± 0.9 | 54.9 ± 1.3
Week 13 | 48.4 ± 10.6 | 49.4 ± 0.3 | | 48.2 ± 0.4 | 49.1 ± 0.5 | 48.5 ± 0.3 | | 48.0 ± 0.5 | 46.7 ± 10.5^†^
Hemoglobin (g/dL)
Day 3 | 14.6 ± 0.1 | 14.5 ± 0.3 | | 14.6 ± 0.3 | 14.5 ± 0.2 | 14.5 ± 0.2 | | 14.7 ± 0.2 | 14.3 ± 0.2
Day 23 | 15.4 ± 0.3 | 15.2 ± 0.2 | | 15.3 ± 0.1 | 15.6 ± 0.2 | 15.5 ± 0.2 | | 15.2 ± 0.2 | 15.4 ± 0.2
Week 13 | 15.3 ± 0.2 | 15.6 ± 0.2 | | 15.9 ± 0.4 | 15.4 ± 0.2 | 15.1 ± 0.1 | | 15.2 ± 0.1 | 14.7 ± 0.1^†^
Erythrocytes (10^6^/µL)
Day 3 | 7.69 ± 0.08 | 7.63 ± 0.14 | | 7.68 ± 0.16 | 7.59 ± 0.10 | 7.53 ± 0.09 | | 7.62 ± 0.12 | 7.40 ± 0.11
Day 23 | 8.13 ± 0.18 | 8.01 ± 0.12 | | 8.03 ± 0.08 | 8.20 ± 0.09 | 8.14 ± 0.10 | | 8.02 ± 0.08 | 8.06 ± 0.11
Week 13 | 8.38 ± 0.12 | 8.59 ± 0.12 | | 8.73 ± 0.23 | 8.53 ± 0.11 | 8.35 ± 0.09 | | 8.33 ± 0.09 | 8.01 ± 0.08^†^
Erythrocyte distribution width (%)
Day 3 | 14.35 ± 0.34 | 14.26 ± 0.19 | | 14.25 ± 0.26 | 14.45 ± 0.26 | 14.23 ± 0.28 | | 14.30 ± 0.37 | 13.96 ± 0.24
Day 23 | 12.08 ± 0.22 | 12.08 ± 0.11 | | 12.36 ± 0.14 | 12.26 ± 0.12 | 12.00 ± 0.11 | | 12.14 ± 0.08 | 12.22 ± 0.12
Week 13 | 11.16 ± 0.10 | 11.17 ± 0.06 | | 11.40 ± 0.19 | 11.21 ± 0.08 | 11.28 ± 0.11 | | 11.11 ± 0.13 | 11.10 ± 0.10
Reticulocytes (%)
Day 3 | 3.86 ± 0.31 | 3.86 ± 0.21 | | 3.77 ± 0.22 | 3.71 ± 0.20 | 3.97 ± 0.19 | | 4.08 ± 0.33 | 3.66 ± 0.17
Day 23 | 2.87 ± 0.17 | 3.11 ± 0.10 | | 2.82 ± 0.11 | 2.52 ± 0.09** | 2.90 ± 0.13 | | 3.03 ± 0.19 | 3.12 ± 0.22
Week 13 | 2.98 ± 0.12 | 2.89 ± 0.10 | | 2.63 ± 0.19 | 3.22 ± 0.14 | 3.14 ± 0.14 | | 3.04 ± 0.18 | 3.23 ± 0.18
Reticulocytes (10^3^/µL)
Day 3 | 295 ± 21 | 295 ± 18 | | 290 ± 20 | 281 ± 14 | 299 ± 15 | | 312 ± 27 | 271 ± 13
Day 23 | 233 ± 15 | 249 ± 9 | | 226 ± 10 | 207 ± 8* | 235 ± 11 | | 242 ± 14 | 252 ± 20
Week 13 | 250 ± 10 | 249 ± 10 | | 230 ± 19 | 274 ± 10 | 262 ± 12 | | 253 ± 15 | 259 ± 14
Nucleated erythrocytes (/100 leukocytes)
Day 3 | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0 | 0.0 ± 0.0
Day 23 | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0 | 0.0 ± 0.0
Week 13 | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | | 0.0 ± 0.0 | 0.0 ± 0.0
Mean cell volume (fL)
Day 3 | 55.4 ± 0.2 | 55.8 ± 0.1 | | 55.2 ± 0.2 | 55.4 ± 0.2 | 55.8 ± 0.2 | | 55.6 ± 0.3 | 55.6 ± 0.3
Day 23 | 54.1 ± 0.2 | 53.7 ± 0.2 | | 53.9 ± 0.2 | 54.4 ± 0.3 | 54.2 ± 0.2 | | 54.2 ± 0.2 | 54.4 ± 0.3
Week 13 | 52.8 ± 0.1 | 52.9 ± 0.2 | | 53.1 ± 0.3 | 52.7 ± 0.2 | 52.4 ± 0.2 | | 52.9 ± 0.2 | 53.0 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 19.0 ± 0.1 | 19.0 ± 0.1 | | 19.0 ± 0.1 | 19.1 ± 0.1 | 19.3 ± 0.1** | | 19.3 ± 0.1* | 19.3 ± 0.1^†^
Day 23 | 19.0 ± 0.1 | 19.0 ± 0.1 | | 19.1 ± 0.1 | 19.0 ± 0.1 | 19.0 ± 0.1 | | 19.0 ± 0.1 | 19.1 ± 0.2
Week 13 | 18.2 ± 0.1 | 18.1 ± 0.1 | | 18.2 ± 0.1 | 18.1 ± 0.1 | 18.1 ± 0.1 | | 18.2 ± 0.1 | 18.3 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 34.3 ± 0.2 | 34.0 ± 0.1 | | 34.5 ± 0.1** | 34.4 ± 0.1* | 34.5 ± 0.1* | | 34.7 ± 0.1** | 34.7 ± 0.2
Day 23 | 35.2 ± 0.1 | 35.2 ± 0.1 | | 35.3 ± 0.1 | 34.9 ± 0.1 | 35.1 ± 0.1 | | 35.0 ± 0.1 | 35.1 ± 0.2
Week 13 | 34.4 ± 0.1 | 34.3 ± 0.1 | | 34.3 ± 0.2 | 34.3 ± 0.1 | 34.4 ± 0.1 | | 34.5 ± 0.1 | 34.6 ± 0.1
Platelets (10^3^/µL)
Day 3 | 767 ± 21 | 759 ± 22 | | 784 ± 17 | 726 ± 21 | 723 ± 15 | | 745 ± 19 | 733 ± 19
Day 23 | 694 ± 12 | 682 ± 23 | | 699 ± 15 | 688 ± 20 | 684 ± 16 | | 688 ± 20 | 708 ± 22
Week 13 | 678 ± 58 | 612 ± 17 | | 602 ± 18 | 621 ± 9 | 620 ± 8 | | 669 ± 21 | 664 ± 15
Mean platelet volume (fL)
Day 3 | 6.500 ± 0.065 | 6.490 ± 0.059 | | 6.470 ± 0.073 | 6.420 ± 0.025 | 6.350 ± 0.031 | | 6.450 ± 0.064 | 6.490 ± 0.098
Day 23 | 6.389 ± 0.123 | 6.256 ± 0.091 | | 6.378 ± 0.080 | 6.233 ± 0.053 | 6.333 ± 0.075 | | 6.330 ± 0.062 | 6.467 ± 0.188
Week 13 | 6.290 ± 0.064 | 6.290 ± 0.038 | | 6.350 ± 0.081 | 6.420 ± 0.065 | 6.400 ± 0.077 | | 6.380 ± 0.089 | 6.290 ± 0.086
Leukocytes (10^3^/µL)
Day 3 | 10.14 ± 0.30 | 9.59 ± 0.33 | | 9.53 ± 0.57 | 9.41 ± 0.33 | 9.85 ± 0.51 | | 10.27 ± 0.44 | 9.59 ± 0.51
Day 23 | 10.64 ± 0.92 | 10.59 ± 0.41 | | 10.74 ± 0.26 | 10.79 ± 0.43 | 10.52 ± 0.70 | | 10.19 ± 0.39 | 9.82 ± 0.47
Week 13 | 9.18 ± 0.72 | 9.13 ± 0.61 | | 7.92 ± 0.47 | 8.46 ± 0.43 | 8.89 ± 0.30 | | 8.51 ± 0.43 | 8.93 ± 0.63
Segmented neutrophils (10^3^/µL)
Day 3 | 2.05 ± 0.05 | 2.02 ± 0.10 | | 2.00 ± 0.22 | 2.02 ± 0.07 | 2.09 ± 0.16 | | 2.15 ± 0.1 | 2.07 ± 0.17
Day 23 | 2.42 ± 0.20 | 2.30 ± 0.08 | | 2.53 ± 0.10 | 2.48 ± 0.07 | 2.42 ± 0.11 | | 2.42 ± 0.11 | 2.38 ± 0.16
Week 13 | 2.38 ± 0.21 | 2.49 ± 0.25 | | 2.36 ± 0.27 | 2.30 ± 0.19 | 2.50 ± 0.25 | | 2.34 ± 0.09 | 2.63 ± 0.25
Bands (10^3^/µL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Metamyelocytes (10^3^/µL)
Day 3 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Week 13 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Myelocytes (10^3^/µL)
Day 3 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Week 13 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000
Lymphocytes (10^3^/µL)
Day 3 | 7.55 ± 0.27 | 7.07 ± .24 | | 7.10 ± 0.36 | 6.90 ± 0.25 | 7.25 ± 0.33 | | 7.58 ± 0.34 | 7.08 ± 0.37
Day 23 | 7.68 ± 0.68 | 7.81 ± 0.31 | | 7.75 ± 0.21 | 7.82 ± 0.33 | 7.59 ± 0.56 | | 7.31 ± 0.29 | 6.99 ± 0.30
Week 13 | 6.39 ± 0.51 | 6.16 ± 0.35 | | 5.17 ± 0.21 | 5.76 ± 0.29 | 5.96 ± 0.15 | | 5.77 ± 0.33 | 5.84 ± 0.35
Atypical lymphocytes (10^3^/µL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00
Monocytes (10^3^/µL)
Day 3 | 0.26 ± 0.01 | 0.26 ± 0.02 | | 0.19 ± 0.02 | 0.22 ± 0.02 | 0.24 ± 0.03 | | 0.24 ± 0.03 | 0.20 ± 0.03^†^
Day 23 | 0.23 ± 0.04 | 0.21 ± 0.02 | | 0.19 ± 0.01 | 0.22 ± 0.03 | 0.22 ± 0.02 | | 0.21 ± 0.01 | 0.21 ± 0.02
Week 13 | 0.20 ± 0.03 | 0.22 ± 0.04 | | 0.17 ± 0.02 | 0.19 ± 0.02 | 0.19 ± 0.02 | | 0.18 ± 0.02 | 0.22 ± 0.04
Basophils (10^3^/µL)
Day 3 | 0.229 ± 0.011 | 0.202 ± 0.012 | | 0.186 ± 0.018 | 0.215 ± 0.020 | 0.220 ± 0.014 | | 0.236 ± 0.023 | 0.185 ± 0.019
Day 23 | 0.221 ± 0.036 | 0.192 ± 0.017 | | 0.181 ± 0.011 | 0.186 ± 0.018 | 0.198 ± 0.023 | | 0.189 ± 0.016 | 0.174 ± 0.021
Week 13 | 0.153 ± 0.023 | 0.183 ± 0.028 | | 0.145 ± 0.022 | 0.153 ± 0.015 | 0.166 ± 0.023 | | 0.149 ± 0.016 | 0.170 ± 0.024
Eosinophils (10^3^/µL)
Day 3 | 0.05 ± 0.01 | 0.04 ± 0.00 | | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | | 0.07 ± 0.01 | 0.06 ± 0.01
Day 23 | 0.09 ± 0.01 | 0.08 ± 0.01 | | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | | 0.08 ± 0.01 | 0.08 ± 0.01
Week 13 | 0.07 ± 0.01 | 0.08 ± 0.01 | | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01 | | 0.06 ± 0.01 | 0.07 ± 0.01
Clinical Chemistry
n | 10 | 10 | | 10 | 10 | 10 | | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 14.1 ± 0.6 | 13.6 ± 0.8 | | 15.2 ± 0.9 | 15.2 ± 0.7 | 13.6 ± 0.5 | | 14.0 ± 0.6 | 13.8 ± 0.7
Day 23 | 17.8 ± 0.9 | 17.8 ± 1.1 | | 18.4 ± 0.9 | 18.3 ± 0.8 | 18.3 ± 0.6 | | 18.4 ± 0.7 | 17.3 ± 0.5
Week 13 | 20.4 ± 0.6 | 21.1 ± 0.6 | | 22.0 ± 0.6 | 22.7 ± 0.7 | 21.1 ± 1.0 | | 21.2 ± 1.1 | 20.6 ± 1.0
Creatinine (mg/dL)
Day 3 | 0.60 ± 0.00 | 0.59 ± 0.01 | | 0.61 ± 0.02 | 0.59 ± 0.01 | 0.60 ± 0.00 | | 0.61 ± 0.01 | 0.61 ± 0.01
Day 23 | 0.64 ± 0.02 | 0.63 ± 0.02 | | 0.62 ± 0.01 | 0.65 ± 0.02 | 0.64 ± 0.02 | | 0.65 ± 0.02 | 0.66 ± 0.02
Week 13 | 0.72 ± 0.01 | 0.66 ± 0.02 | | 0.69 ± 0.02 | 0.68 ± 0.06 | 0.68 ± 0.01 | | 0.68 ± 0.01 | 0.71 ± 0.02
Total protein (g/dL)
Day 3 | 5.6 ± 0.1 | 5.5 ± 0.2 | | 5.6 ± 0.2 | 5.4 ± 0.1 | 5.5 ± 0.0 | | 5.6 ± 0.1 | 5.4 ± 0.1^†^
Day 23 | 6.3 ± 0.1 | 6.3 ± 0.1 | | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.4 ± 0.1 | | 6.3 ± 0.1 | 6.4 ± 0.1
Week 13 | 7.2 ± 0.1 | 7.1 ± 0.1 | | 7.2 ± 0.1 | 7.6 ± 0.1* | 7.3 ± 0.1 | | 7.3 ± 0.1 | 7.4 ± 0.1
Albumin (g/dL)
Day 3 | 3.6 ± 0.0 | 3.6 ± 0.1 | | 3.6 ± 0.1 | 3.6 ± 0.0 | 3.6 ± 0.0 | | 3.6 ± 0.1 | 3.5 ± 0.1
Day 23 | 3.9 ± 0.1 | 3.8 ± 0.0 | | 3.8 ± 0.0 | 3.9 ± 0.1 | 3.9 ± 0.1 | | 3.8 ± 0.1 | 3.8 ± 0.0
Week 13 | 4.0 ± 0.1 | 4.0 ± 0.1 | | 4.1 ± 0.1 | 4.0 ± 0.2 | 4.0 ± 0.1 | | 4.0 ± 0.1 | 4.0 ± 0.1
Alanine aminotransferase (IU/L)
Day 3 | 69 ± 2 | 62 ± 2 | | 62 ± 3 | 65 ± 2 | 67 ± 1 | | 67 ± 1 | 68 ± 2
Day 23 | 52 ± 1 | 49 ± 1 | | 49 ± 1 | 50 ± 2 | 50 ± 2 | | 52 ± 2 | 50 ± 2
Week 13 | 70 ± 2 | 74 ± 4 | | 71 ± 3 | 65 ± 2 | 58 ± 2** | | 55 ± 3** | 50 ± 1^††^
Alkaline phosphatase (IU/L)
Day 3 | 679 ± 17 | 626 ± 17 | | 628 ± 12 | 650 ± 11 | 640 ± 14 | | 642 ± 13 | 576 ± 16^††^
Day 23 | 471 ± 9 | 462 ± 11 | | 479 ± 12 | 471 ± 9 | 446 ± 15 | | 438 ± 11 | 395 ± 7^††^
Week 13 | 350 ± 13 | 360 ± 13 | | 334 ± 28 | 367 ± 13 | 344 ± 13 | | 282 ± 7** | 259 ± 10^††^
Creatine kinase (IU/L)
Day 3 | 661 ± 43 | 633 ± 65 | | 876 ± 56* | 676 ± 53 | 541 ± 45 | | 729 ± 46 | 666 ± 80
Day 23 | 723 ± 181 | 733 ± 75 | | 984 ± 148 | 556 ± 114 | 862 ± 110 | | 928 ± 141 | 806 ± 163
Week 13 | 326 ± 63 | 325 ± 29 | | 257 ± 38 | 250 ± 30 | 326 ± 58 | | 277 ± 32 | 244 ± 41
Sorbitol dehydrogenase (IU/L)
Day 3 | 41 ± 3 | 40 ± 3 | | 33 ± 4 | 40 ± 4 | 46 ± 3 | | 42 ± 3 | 40 ± 4
Day 23 | 41 ± 4 | 38 ± 3 | | 31 ± 4 | 49 ± 6 | 36 ± 5 | | 36 ± 6 | 39 ± 5
Week 13 | 56 ± 5 | 49 ± 5 | | 52 ± 5 | 58 ± 3 | 47 ± 3 | | 49 ± 5 | 46 ± 4
Bile acids (µmol/L)
Day 3 | 24.6 ± 1.9 | 33.4 ± 4.4 | | 30.3 ± 2.9 | 28.0 ± 4.7 | 27.4 ± 3.9 | | 26.7 ± 3.9 | 23.3 ± 5.2
Day 23 | 34.8 ± 4.4 | 31.3 ± 5.2 | | 38.1 ± 4.9 | 33.8 ± 4.1 | 29.8 ± 3.2 | | 34.0 ± 1.9 | 30.1 ± 1.6
Week 13 | 24.8 ± 4.2 | 21.7 ± 3.0 | | 26.7 ± 4.6 | 19.0 ± 2.0 | 18.3 ± 1.5 | | 14.5 ± 1.0 | 14.7 ± 0.8^†^

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

† Significantly different (P ≤ 0.05) from the untreated control group by Wilcoxon’s rank sum test.

†† P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data. Statistical comparisons between the two control groups are not presented.

^b^ n = 9.

Table B-2 Protein Yield and CYP2E1 Activity in the Liver of Rats in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
n | 5 | 5 | 5 | 5 | 5 | 5 | 5
Male
Total microsomal protein (mg/kg liver)
Day 23 | 13.28 ± 1.62 | 10.81 ± 0.76 | 13.69 ± 1.72 | 11.74 ± 1.09 | 15.08 ± 1.11* | 18.10 ± 0.93** | 18.82 ± 2.32
Week 13 | 10.004 ± 0.370 | 13.51 ± 1.818 | 14.200 ± 1.243 | 13.414 ± 1.138 | 12.300 ± 0.628 | 10.938 ± 1.044^b^ | 11.338 ± 0.819
CYP2E1 liver activity (nmol/minute per mg protein)
Day 23 | 0.443 ± 0.035 | 0.403 ± 0.058 | 0.437 ± 0.024 | 0.446 ± 0.047 | 0.454 ± 0.026 | 0.432 ± 0.029 | 0.414 ± 0.017
Week 13 | 0.472 ± 0.022 | 0.419 ± 0.030 | 0.497 ± 0.032 | 0.452 ± 0.011 | 0.414 ± 0.026 | 0.527 ± 0.086 | 0.555 ± 0.819
Female
Total microsomal protein (mg/kg liver)
Day 23 | 13.20 ± 1.54 | 15.70 ± 0.74 | 11.64 ± 0.47* | 14.96 ± 1.15 | 15.46 ± 1.28 | 15.56 ± 0.54 | 16.42 ± 1.34
Week 13 | 7.686 ± 0.657 | 7.412 ± 0.610 | 8.342 ± 0.509 | 9.344 ± 0.169* | 10.496 ± 0.849** | 13.280 ± 0.684** | 12.100 ± 0.536^††^
CYP2E1 liver activity (nmol/minute per mg protein)
Day 23 | 0.227 ± 0.020 | 0.216 ± 0.034 | 0.232 ± 0.018 | 0.270 ± 0.032 | 0.247 ± 0.053 | 0.225 ± 0.026 | 0.286 ± 0.027
Week 13 | 0.528 ± 0.097 | 0.336 ± 0.022 | 0.336 ± 0.021 | 0.365 ± 0.018 | 0.362 ± 0.020 | 0.370 ± 0.030 | 0.470 ± 0.050

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^††^ Significantly different (P ≤ 0.01) from the untreated control group by Wilcoxon’s rank sum test.

^a^ Data are presented as mean ± standard error. Statistical comparisons between the two control groups are not presented.

^b^ n = 4.

Table B-3 Hematology Data for Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | | Vehicle Control | | 6.25% | | 12.5% | 25% | 50% | 100%
Male
n | 10 | | 10 | | | 10 | 10 | 10 | 10 | 10
Hematocrit (auto) (%)
| 52.3 ± 0.9 | | 53.3 ± 0.7 | | | 52.0 ± 1.3 | 51.2 ± 0.9 | 48.7 ± 0.8** | 49.1 ± 0.8** | 45.7 ± 0.8^††^
Hematocrit (spun) (%)
| 52.9 ± 1.0 | | 54.5 ± 0.7 | | | 53.7 ± 1.4 | 51.8 ± 0.7* | 49.7 ± 1.1** | 51.3 ± 0.9** | 47.6 ± 1.1^††^
Hemoglobin (g/dL)
| 16.7 ± 0.4 | | 17.0 ± 0.2 | | | 16.7 ± 0.4 | 16.5 ± 0.3 | 15.7 ± 0.3** | 16.0 ± 0.2** | 15.0 ± 0.3^††^
Erythrocytes (10^6^/µL)
| 10.76 ± 0.22 | | 10.84 ± 0.13 | | | 10.56 ± 0.24 | 10.45 ± 0.17 | 9.94 ± 0.16** | 9.98 ± 0.16** | 9.26 ± 0.13^††^
Erythrocyte distribution width (%)
| 12.63 ± 0.18 | | 12.17 ± 0.07 | | | 12.53 ± 0.11 | 12.34 ± 0.11 | 12.67 ± 0.13** | 12.92 ± 0.15** | 13.42 ± 0.12^††^
Reticulocytes (%)
| 3.030 ± 0.141 | | 3.37 ± 0.12 | | | 3.27 ± 0.16 | 2.90 ± 0.18 | 3.10 ± 0.25 | 3.06 ± 0.14 | 3.100 ± 0.190
Reticulocytes (10^3^/µL)
| 325 ± 15 | | 366 ± 16 | | | 346 ± 19 | 305 ± 23 | 308 ± 26 | 304 ± 11 | 287 ± 19
Nucleated erythrocytes (/100 leukocytes)
| 0.0 ± 0.0 | | 0.00 ± 0.00 | | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.0 ± 0.0
Mean cell volume (fL)
| 48.6 ± 0.3 | | 49.2 ± 0.2 | | | 49.2 ± 0.2 | 48.9 ± 0.2 | 48.9 ± 0.1 | 49.2 ± 0.2 | 49.3 ± 0.3
Mean cell hemoglobin (pg)
| 15.5 ± 0.1 | | 15.7 ± 0.0 | | | 15.8 ± 0.1 | 15.8 ± 0.1 | 15.8 ± 0.0 | 16.0 ± 0.0** | 16.2 ± 0.1^††^
Mean cell hemoglobin concentration (g/dL)
| 31.9 ± 0.2 | | 31.9 ± 0.1 | | | 32.1 ± 0.1 | 32.2 ± 0.2 | 32.2 ± 0.1* | 32.5 ± 0.1** | 32.7 ± 0.1^††^
Platelets (10^3^/µL)
| 688 ± 21 | | 666 ± 23 | | | 620 ± 31 | 663 ± 26 | 716 ± 31 | 747 ± 16* | 843 ± 37^††^
Mean platelet volume (fL)
| 5.490 ± 0.120 | | 5.490 ± 0.041 | | | 5.360 ± 0.108 | 5.460 ± 0.064 | 5.570 ± 0.122 | 5.540 ± 0.070 | 5.410 ± 0.043
Leukocytes (10^3^/µL)
| 5.48 ± 0.59 | | 6.22 ± 0.43 | | | 5.47 ± 0.50 | 5.96 ± 0.66 | 5.30 ± 0.59 | 6.51 ± 0.54 | 5.78 ± 0.62
Segmented neutrophils (10^3^/µL)
| 1.23 ± 0.14 | | 1.45 ± 0.10 | | | 1.29 ± 0.14 | 1.47 ± 0.17 | 1.22 ± 0.13 | 1.71 ± 0.21 | 1.87 ± 0.33
Bands (10^3^/µL)
| 0.00 ± 0.00 | | 0.00 ± 0.00 | | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Metamyelocytes (10^3^/µL)
| 0.000 ± 0.000 | | 0.000 ± 0.000 | | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Myelocytes (10^3^/µL)
| 0.000 ± 0.000 | | 0.000 ± 0.000 | | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lymphocytes (10^3^/µL)
| 4.19 ± 0.47 | | 4.71 ± 0.33 | | | 4.13 ± 0.36 | 4.43 ± 0.49 | 4.01 ± 0.47 | 4.72 ± 0.42 | 3.83 ± 0.36
Atypical lymphocytes (10^3^/µL)
| 0.00 ± 0.00 | | 0.00 ± 0.00 | | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Monocytes (10^3^/µL)
| 0.04 ± 0.01 | | 0.04 ± 0.00 | | | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01* | 0.06 ± 0.01
Basophils (10^3^/µL)
| 0.007 ± 0.002 | | 0.008 ± 0.001 | | | 0.003 ± 0.002 | 0.004 ± 0.002 | 0.004 ± 0.002 | 0.005 ± 0.002 | 0.008 ± 0.001
Eosinophils (10^3^/µL)
| 0.01 ± 0.00 | | 0.02 ± 0.00 | | | 0.01 ± 0.00 | 0.02 ± 0.01 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.01 ± 0.00
Female
n | 10 | | 10 | | 10 | | 10 | 10 | 10 | 10
Hematocrit (auto) (%)
| 50.4 ± 2.2 | | 48.7 ± 1.9 | | 48.0 ± 1.5 | | 49.7 ± 1.2 | 49.3 ± 0.4 | 46.4 ± 0.7 | 43.6 ± 1.1^†^
Hematocrit (spun) (%)
| 54.9 ± 1.3 | | 52.2 ± 1.0 | | 51.3 ± 0.4 | | 51.5 ± 1.2 | 51.0 ± 0.6 | 48.1 ± 0.5** | 46.9 ± 0.7^††^
Hemoglobin (g/dL)
| 16.5 ± 0.7 | | 15.9 ± 0.6 | | 15.9 ± 0.5 | | 16.3 ± 0.4 | 16.3 ± 0.2 | 15.4 ± 0.2 | 14.6 ± 0.4^†^
Erythrocytes (10^6^/µL)
| 10.42 ± 0.45 | | 10.04 ± 0.36 | | 9.93 ± 0.29 | | 10.13 ± 0.22 | 10.16 ± 0.11 | 9.48 ± 0.10 | 8.93 ± 0.22^††^
Erythrocyte distribution width (%)
| 12.21 ± 0.14 | | 12.24 ± 0.08 | | 12.61 ± 0.09* | | 12.65 ± 0.11** | 13.03 ± 0.08** | 13.35 ± 0.15** | 13.35 ± 0.12^††^
Reticulocytes (%)
| 2.810 ± 0.104 | | 3.03 ± 0.19 | | 3.30 ± 0.16 | | 3.50 ± 0.12 | 3.10 ± 0.16 | 3.51 ± 0.30 | 3.01 ± 0.16
Reticulocytes (10^3^/µL)
| 295 ± 20 | | 303 ± 19 | | 326 ± 15 | | 354 ± 11 | 315 ± 18 | 332 ± 28 | 270 ± 17
Nucleated erythrocytes (/100 leukocytes)
| 0.0 ± 0.0 | | 0.0 ± 0.0 | | 0.0 ± 0.0 | | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Mean cell volume (fL)
| 48.6 ± 0.2 | | 48.5 ± 0.3 | | 48.2 ± 0.3 | | 49.0 ± 0.3 | 48.6 ± 0.3 | 48.9 ± 0.4 | 48.9 ± 0.2
Mean cell hemoglobin (pg)
| 15.9 ± 0.0 | | 15.9 ± 0.1 | | 16.0 ± 0.1 | | 16.1 ± 0.1 | 16.0 ± 0.0 | 16.2 ± 0.1 | 16.4 ± 0.1^††^
Mean cell hemoglobin concentration (g/dL)
| 32.9 ± 0.1 | | 32.7 ± 0.2 | | 33.1 ± 0.1 | | 32.8 ± 0.1 | 33.0 ± 0.1 | 33.2 ± 0.2* | 33.5 ± 0.1^††^
Platelets (10^3^/µL)
| 528 ± 37 | | 577 ± 39 | | 595 ± 26 | | 608 ± 29 | 641 ± 28 | 699 ± 34* | 818 ± 30^††^
Mean platelet volume (fL)
| 5.910 ± 0.095 | | 5.860 ± 0.180 | | 5.740 ± 0.079 | | 5.870 ± 0.116 | 5.680 ± 0.053 | 5.620 ± 0.051 | 5.840 ± 0.078
Leukocytes (10^3^/µL)
| 5.79 ± 0.46 | | 6.17 ± 0.29 | | 6.83 ± 0.26 | | 6.25 ± 0.40 | 6.97 ± 0.61 | 6.98 ± 0.63 | 6.61 ± 0.50
Segmented neutrophils (10^3^/µL)
| 1.28 ± 0.11 | | 1.41 ± 0.09 | | 1.64 ± 0.06 | | 1.44 ± 0.13 | 1.54 ± 0.16 | 1.63 ± 0.13 | 1.68 ± 0.17
Bands (10^3^/µL)
| 0.00 ± 0.00 | | 0.00 ± 0.00 | | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Metamyelocytes (10^3^/µL)
| 0.000 ± 0.000 | | 0.000 ± 0.000 | | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Myelocytes (10^3^/µL)
| 0.000 ± 0.000 | | 0.000 ± 0.000 | | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lymphocytes (10^3^/µL)
| 4.44 ± 0.36 | | 4.68 ± 0.20 | | 5.11 ± 0.22 | | 4.71 ± 0.28 | 5.34 ± 0.45 | 5.25 ± 0.50 | 4.80 ± 0.37
Atypical lymphocytes (10^3^/µL)
| 0.00 ± 0.00 | | 0.00 ± 0.00 | | 0.00 ± 0.00 | | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Monocytes (10^3^/µL)
| 0.04 ± 0.00 | | 0.04 ± 0.01 | | 0.06 ± 0.00 | | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01** | 0.09 ± 0.01^††^
Basophils (10^3^/µL)
| 0.006 ± 0.002 | | 0.011 ± 0.003 | | 0.006 ± 0.002 | | 0.014 ± 0.005 | 0.006 ± 0.002 | 0.009 ± 0.002 | 0.008 ± 0.001
Eosinophils (10^3^/µL)
| 0.02 ± 0.00 | | 0.03 ± 0.01 | | 0.02 ± 0.00 | | 0.03 ± 0.01 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.03 ± 0.00

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^†^ Significantly different (P ≤ 0.05) from the untreated control group by Wilcoxon’s rank sum test.

^††^ P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data. Statistical comparisons between the two control groups are not presented.

Table B-4 CYP2E1 Activity in the Liver of Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
n | 4 | 5 | 5 | 3 | 5 | 5 | 5
Male
CYP2E1 liver activity (nmol/minute per mg protein)
| 1.940 ± 0.131 | 1.883 ± 0.185^b^ | 2.193 ± 0.098^c^ | 2.063 ± 0.182 | 2.542 ± 0.177* | 2.940 ± 0.100** | 3.482 ± 0.084^††^
Female
CYP2E1 liver activity (nmol/minute per mg protein)
| 1.855 ± 0.146 | 1.782 ± 0.127 | 2.250 ± 0.086* | 2.677 ± 0.090** | 2.742 ± 0.068** | 2.940 ± 0.149**^b^ | 2.780 ± 0.177^††^

* Significantly different (P ≤ 0.05) from the vehicle control group by Shirley’s test.

** P ≤ 0.01.

^††^ Significantly different (P ≤ 0.01) from the untreated control group by Wilcoxon’s rank sum test.

^a^ Data are presented as mean ± standard error. Statistical comparisons between the two control groups are not presented.

^b^ n = 4.

^c^ n = 3.